# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 4-Methylcyclohexanemethanol

4-Methylcyclohexanemethanol (MCHM) was obtained from TCI America (Portland, OR) in one lot (KDY3F) that was used in the dose range-finding study and the prenatal developmental toxicity study. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO) for the study laboratory at Southern Research (Birmingham, AL). Reports on analyses performed in support of the MCHM studies are on file at the National Institute of Environmental Health Sciences.

Lot KDY3F of the test chemical, a clear colorless liquid, was identified as MCHM using Fourier transform infrared (FTIR), proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy, and gas chromatography (GC) with mass spectrometry (MS) detection. In addition, boiling point, density, and octanol:water partition coefficient were measured. All spectra were consistent with isomers of the proposed structure and literature spectra of MCHM.^72-75^ Two components tentatively identified as cis- and trans-isomers of MCHM were observed for the test article using GC/MS. Representative FTIR and FT proton NMR spectra are presented in Figure A-1 and Figure A-2, respectively. The boiling point of the test chemical was 199.4°C (consistent with a literature reference value of 202°C^76^), the relative density was 0.9203 g/mL, and the octanol:water partition coefficient was 353 (resulting in a log P of 2.55).

The moisture content of lot KDY3F was determined using Karl Fischer titration. Elemental analyses for carbon, hydrogen, and nitrogen were conducted by Galbraith Laboratories, Inc. (Knoxville, TN). The purity profile was determined using GC with flame ionization detection (FID) and two columns with differing polarities.

For lot KDY3F, Karl Fischer titration indicated 0.209% water. Elemental analyses for carbon, hydrogen, and nitrogen were consistent with the theoretical values for MCHM. GC/FID analysis by system A (Table A-1) detected two major peaks with a combined area of 99.97% of the total peak area and no impurities with areas ≥0.05% of the total peak area. The relative areas of the two major peaks indicated that MCHM consisted of 67.99% cis- and 31.98% trans-isomers. GC/FID by system B detected two major peaks with a combined relative area of 99.83% (with relative areas of 67.80% [cis-] and 32.03% [trans-] isomers), and two minor impurities totaling 0.13% of the total peak area. The overall purity of lot KDY3F was determined to be greater than or equal to 99.8%.

Stability studies of the bulk chemical were conducted using GC/FID by a system similar to system A. These studies indicated that MCHM was stable as a bulk chemical for 2 weeks when stored in amber glass vials under an inert headspace, sealed with aluminum caps with Teflon^®^-lined septa at temperatures up to 60°C. To ensure stability, the bulk chemical was stored at room temperature under an inert headspace in amber glass bottles. Reanalyses of the bulk chemical were performed during the animal studies by the analytical chemistry laboratory using FTIR and GC/FID by system C and no degradation of the bulk chemical was detected.

### A.1.2 Corn Oil

Corn oil was obtained from Spectrum Laboratory Products, Inc. (Gardena, CA), in two lots (ICK0678 and 2DG0376) that were used as the vehicle in the dose range-finding and prenatal developmental toxicity studies, respectively. A solubility study of MCHM was performed by the analytical chemistry laboratory; after 17 days under refrigerated conditions, the test article remained soluble in corn oil at up to 600 mg/mL with no remixing required. Both lots contained peroxide levels less than the rejection level of 3 meQ/kg corn oil.

## A.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared once for the dose range-finding study and once for the prenatal developmental toxicity study by mixing the appropriate amount of MCHM with corn oil to give the required concentrations (Table A-2). The dose formulations were stored at room temperature in amber glass bottles with Teflon-lined caps, protected from light, for up to 27 days (dose range-finding study) or 39 days (prenatal developmental toxicity study).

Stability studies of 0.20 and 2.0 mg/mL formulations were performed by the analytical chemistry laboratory with GC/FID by system C (Table A-1). For the 0.2 mg/mL formulation, stability was confirmed for at least 42 days during which the formulation was stored under ambient or refrigerated conditions and protected from light, and for 3 hours under simulated animal room conditions. In addition, for the 2.0 mg/mL formulation, stability was confirmed for at least 44 days during which it was stored under ambient or refrigerated conditions and protected from light.

Analyses of the dose formulations of MCHM were conducted by the analytical chemistry laboratory using GC/FID by system C. During the dose range-finding study, the dose formulations were analyzed once; all four dose formulations were within 10% of the target concentrations (Table A-3). Animal room samples of these dose formulations were also analyzed; all four animal room samples were within 10% of the target concentrations. During the prenatal developmental toxicity study, the dose formulations were analyzed once; animal room samples of these dose formulations were analyzed twice (Table A-4). All four dose formulations analyzed were within 10% of the target concentrations and all eight animal room samples were within 10% of the target concentrations.

Figure A-1

Fourier Transform Infrared Absorption Spectrum of 4-Methylcyclohexanemethanol

Figure A-2

Fourier Transform Proton Nuclear Magnetic Resonance Spectrum of 4-Methylcyclohexanemethanol

Table A-1 Gas Chromatography Systems Used in the Gavage Studies of 4-Methylcyclohexanemethanol^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame Ionization | Zebron™ ZB-624, 30 m × 0.53 mm, 3.0 µm film (Phenomenex, Torrance, CA) | Helium at 5 mL/minute | 50°C for 2 minutes, then 10°C/minute to 240°C, held for 4 minutes
System B
Flame Ionization | Agilent DB-1, 30 m × 0.53 mm, 1.5 µm film (Agilent Technologies, Inc., Santa Clara, CA) | Helium at 5 mL/minute | 50°C for 2 minutes, then 10°C/minute to 240°C, held for 4 minutes
System C
Flame Ionization | Rtx^®^-VMS, 30 m × 0.53 mm, 3.0 µm film (Restek, Bellefonte, PA) | Helium at 5 mL/minute | 50°C for 2 minutes, then 10°C/minute to 240°C, held for 4 minutes

^a^ The gas chromatographs were manufactured by Agilent Technologies, Inc. (Santa Clara, CA).

Table A-2 Preparation and Storage of Dose Formulations in the Gavage Studies of 4-Methylcyclohexanemethanol

Dose Range-finding Study | Prenatal Developmental Toxicity Study
Preparation
The appropriate amounts of 4-methylcyclohexanemethanol were weighed into 500 mL volumetric flasks, diluted to near volume with corn oil, swirled to dissolve, diluted to volume with corn oil, mixed by inversion, and then stirred with a magnetic stir bar for 30 minutes. The dose formulations were prepared once. | Same as the dose range-finding study except that the formulations were prepared in 1 L volumetric flasks
Chemical Lot Number
KDY3F | KDY3F
Maximum Storage Time
27 days | 39 days
Storage Conditions
Stored in amber glass bottles with Teflon^®^-lined caps, protected from light, at room temperature | Stored in amber glass bottles with Teflon^®^-lined caps, protected from light, at room temperature
Study Laboratory
Southern Research (Birmingham, AL) | Southern Research (Birmingham, AL)

Table A-3 Results of Analyses of Dose Formulations Administered to Female Rats in the Dose Range-Finding Gavage Study of 4-Methylcyclohexanemethanol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
August 13, 2014 | August 13, 2014 | 75 | 75.82 | +1
| | 150 | 152.0 | +1
| | 300 | 303.5 | +1
| | 450 | 456.0 | +1
| September 11, 2014^b^ | 75 | 75.36 | 0
| | 150 | 152.1 | +1
| | 300 | 302.6 | +1
| | 450 | 448.5 | 0

^a^ Results of triplicate analyses. Dosing volume = 2 mL/kg; 75 mg/mL = 150 mg/kg, 150 mg/mL = 300 mg/kg, 300 mg/mL = 600 mg/kg; 450 mg/mL = 900 mg/kg.

^b^ Animal room samples.

Table A-4 Results of Analyses of Dose Formulations Administered to Female Rats in the Prenatal Developmental Toxicity Gavage Study of 4-Methylcyclohexanemethanol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
October 30, 2014 | October 30, 2014 | 25 | 24.78 | −1
| | 50 | 49.67 | −1
| | 100 | 99.84 | 0
| | 200 | 199.3 | 0
| December 3, 2014^b^ | 25 | 24.88 | 0
| | 50 | 50.57 | +1
| | 100 | 100.5 | +1
| | 200 | 199.6 | 0
| December 10, 2014^b^ | 25 | 25.00 | 0
| | 50 | 50.09 | 0
| | 100 | 99.83 | 0
| | 200 | 200.1 | 0

^a^ Results of triplicate analyses. Dosing volume = 2 mL/kg; 25 mg/mL = 50 mg/kg, 50 mg/mL = 100 mg/kg, 100 mg/mL = 200 mg/kg, 200 mg/mL = 400 mg/kg.

^b^ Animal room samples.