# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2690-2052

DOI: https://doi.org/10.22427/NTP-DART-01

Report Series: NTP Developmental and Reproductive Toxicity Report Series

Report Series Number: 01

Official citation: National Toxicology Program (NTP). 2020. NTP developmental and reproductive toxicity technical report on the prenatal development studies of tris(chloropropyl) phosphate (CASRN 13674-84-5) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (gavage studies). Research Triangle Park, NC: National Toxicology Program. DART Report 01.