# References

1 National Toxicology Program (NTP). Tris(chloropropyl)phosphate – M20263. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2016. https://ntp.niehs.nih.gov/testing/status/agents/ts-m20263.html [Accessed: November 16, 2016]
2 U.S. Environmental Protection Agency (USEPA). TSCA work plan chemical problem formulation and initial assessment: Chlorinated phosphate ester cluster flame retardants. Washington, DC: U.S. Environmental Protection Agency, Office of Chemical Safety and Pollution Prevention, Office of Pollution Prevention and Toxics; 2015. EPA Document No. EPA/740/R-15/001.
3 U.S. Environmental Protection Agency (USEPA). Flame retardants used in flexible polyurethane foam: An alternatives assessment update. Washington, DC: U.S. Environmental Protection Agency; 2015. EPA Document No. EPA/744/R-15/002.
4 National Research Council (NRC). Toxicological risks of selected flame-retardant chemicals. Washington (DC): National Academies Press; 2000.
5 European Union (EU). Tris(2 chloro-1 methylethyl) Phosphate (TCPP), (CAS No. 13674-84-5, EINECS No. 237-158-7) risk assessment. Luxembourg: Office for Official Publications of the European Communities; 2008.
6 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for phosphate ester flame retardants. Atlanta (GA): U.S. Department of Health and Human Services, Public Health Service, Agency for Toxic Substances and Disease Registry; 2012.
7 U.S. Environmental Protection Agency (USEPA). 2012 Chemical Data Reporting (CDR): 2-propanol, 1-chloro, 2,2ʹ2˝-phosphate. Washington (DC): U.S. Environmental Protection Agency, Office of Chemical Safety and Pollution Prevention, Office of Pollution Prevention and Toxics; 2012.
8 Wilczynski SL Killinger JM Zwicker GM Freudenthal RI Fyrol FR-2 fertility study in male rabbits. Toxicologist. 1983; 3:22.
9 World Health Organization (WHO). Flame retardants: Tris(chloropropyl) phosphate and tris(2-chloroethyl) phosphate. Geneva, Switzerland: World Health Organization; 1998. Environmental Health Criteria 209.
10 U.S. Environmental Protection Agency (USEPA). Substance Registry Service (SRS): Chemical and substance resources. Washington, DC: U.S. Environmental Protection Agency; 2016. https://iaspub.epa.gov/sor_internet/registry/substreg/searchandretrieve/substancesearch/search.do [Accessed: November 16, 2016]
11 Organisation for Economic Co-operation and Development (OECD). Screening Information Dataset (SIDS) initial assessment profile: Tris(1-chloro-2-propyl)phosphate, CAS No: 13674-84-5. Geneva, Switzerland: UNEP Chemicals, UNEP Publications; 2000.
12 U.S. Environmental Protection Agency (USEPA). Reducing your child’s exposure to flame retardant chemicals. Washington, DC: U.S. Environmental Protection Agency; 2016. EPA Document No. EPA/740/16/001.
13 European Chemicals Agency (ECHA). Substance information: Tris (2-chloro-1-methylethyl) phosphate. 2016. https://echa.europa.eu/substance-information/-/substanceinfo/100.033.766
14 Minegishi KI, Kurebayashi H, Nambaru S, Morimoto K, Takahashi T, Yamaha T. Comparative studies on absorption, distribution, and excretion of flame retardants halogenated alkyl phosphate in rats. Eisei Kagaku. 1988; 34(2):102-114. 10.1248/jhs1956.34.102
15 Van den Eede N Maho W Erratico C Neels H Covaci A First insights in the metabolism of phosphate flame retardants and plasticizers using human liver fractions. Toxicol Lett. 2013; 223(1):9–15. 10.1016/j.toxlet.2013.08.012 23994729
16 Kawasaki H Murai T Kanoh S Studies on the toxicity of insecticides and food additives in pregnant rats. V. Fetal toxicity of tris-(chloropropyl) phosphate (TCPP) [In Japanese]. Oyo Yakuri. 1982; 24:697–702.
17 National Industrial Chemicals Notification Assessment Scheme (NICNAS). Inventory Multi-tiered Assessment and Prioritisation (IMAP): Human health tier II assessment for 2 propanol, 1 chloro, phosphate (3:1). Australia: Australian Government, Department of Health, National Industrial Chemicals Notification and Assessment Scheme; 2016. https://www.nicnas.gov.au/chemical-information/imap-assessments/imap-assessment-details?assessment_id=1891 [Accessed: August 1, 2016]
18 Freudenthal RI Henrich RT A subchronic toxicity study of Fyrol PCF in Sprague-Dawley rats. Int J Toxicol. 1999; 18(3):173–176. 10.1080/109158199225468
19 National Toxicology Program (NTP). TOX-tbd - tris(chloropropyl)phosphate (TCPP). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program, Chemical Effects in Biological Systems; 2016. http://tools.niehs.nih.gov/cebs3/views/?action=main.dataReview&bin_id=1660 [Accessed: August 1, 2016]
20 National Toxicology Program (NTP). Nominated substances. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2005. https://ntp.niehs.nih.gov/ntp/htdocs/chem_background/exsumpdf/cpscfrsnomination_supp_062_508.pdf [Accessed: November 16, 2016]
21 Chernoff N Setzer RW Miller DB Rosen MB Rogers JM Effects of chemically induced maternal toxicity on prenatal development in the rat. Teratology. 1990; 42(6):651–658. 10.1002/tera.1420420610 2087686
22 U.S. Environmental Protection Agency (USEPA). Guidelines for developmental toxicity risk assessment. Washington, DC: U.S. Environmental Protection Agency, Risk Assessment Forum; 1991. EPA Document No. EPA/600/FR-91/001.
23 Tyl RW Commentary on the role of maternal toxicity on developmental toxicity. Birth Defects Res B Dev Reprod Toxicol. 2012; 95(3):262–266. 10.1002/bdrb.21015 22706915
24 Organisation for Economic Co-operation and Development (OECD). OECD guideline for the testing of chemicals: Proposal for updating guideline 414. Prenatal developmental toxicity study. Paris, France: Organisation for Economic Co-operation and Development; 2001.
25 Makris SL Solomon HM Clark R Shiota K Barbellion S Buschmann J Ema M Fujiwara M Grote K Hazelden KP Terminology of developmental abnormalities in common laboratory mammals (version 2). Congenit Anom (Kyoto). 2009; 49(3):123–246. 10.1111/j.1741-4520.2009.00239.x 20002907
26 National Institute of Standards and Technology (NIST). NIST/EPA/NIH mass spectral library (NIST 08) and NIST mass spectral search program (version 2.0f). Gaithersburg (MD): U.S. Department of Commerce, National Institute of Standards and Technology; 2008.
27 Suckow MA Weisbroth SH Franklin CL The laboratory rat. 2nd ed. Amsterdam, Netherlands: Elsevier; 2006.
28 Hayes AW Kruger CL Hayes’ principles and methods of toxicology. 6th ed. Boca Raton (FL): CRC Press; 2014. p. 1670–1672. 10.1201/b17359
29 Salewski E Färbemethode zum makroskopischen nachweis von implantationsstellen am uterus der ratte. Naunyn Schmiedebergs Arch Pharmacol. 1964; 247(4):367. 10.1007/BF02308461
30 Staples RE Detection of visceral alterations in mammalian fetuses. Teratology. 1974; 9:A37–A38.
31 Stuckhardt JL Poppe SM Fresh visceral examination of rat and rabbit fetuses used in teratogenicity testing. Teratog Carcinog Mutagen. 1984; 4(2):181–188. 10.1002/tcm.1770040203 6145223
32 Thompson RF Basic neuroanatomy. Foundations of Physiological Psychology. New York (NY): Harper and Row Publishers; 1967. p. 79–82.
33 Marr MC Price CJ Myers CB Morrissey RE Developmental stages of the CD®(Sprague‐Dawley) rat skeleton after maternal exposure to ethylene glycol. Teratology. 1992; 46(2):169–181. 10.1002/tera.1420460210 1440420
34 Tyl RW Marr MC Developmental toxicity texting – methodology. Developmental and Reproductive Toxicology. 2nd ed. New York (NY): Taylor and Francis Group; 2006. p. 201–261.
35 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.10.1080/01621459.1955.10501294
36 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27:103–117. 10.2307/2528930 5547548
37 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28:519–531. 10.2307/2556164 5037867
38 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33:386–389. 10.2307/2529789 884197
39 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42:183–186. 10.2307/2531254 3719054
40 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
41 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. 10.2307/2333011
42 Dixon WJ Massey FJ Jr Introduction to statistical analysis. 2nd ed. New York (NY): McGraw-Hill Book Company, Inc; 1957. p. 276–278, 412.
43 Hsu JC The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168.
44 Armitage P Tests for linear trends in proportions and frequencies. Biometrics. 1955; 11(3):375–386. 10.2307/3001775
45 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
46 Zorrilla EP. Multiparous species present problems (and possibilities) to developmentalists. Dev Psychobiol. 1997; 30(2):141-150. 10.1002/(SICI)1098-2302(199703)30:2<141:AID-DEV5>3.0.CO;2-Q
47 Pendergast JF Gagne SJ Lindstrom MJ Correlated binary data. In: Encyclopedia of Biostatistics. London, UK: John Wiley & Sons, Ltd; 2005. 10.1002/0470011815.b2a10018
48 Li B Lingsma HF Steyerberg EW Lesaffre E Logistic random effects regression models: A comparison of statistical packages for binary and ordinal outcomes. BMC Med Res Methodol. 2011; 11(1):77. 10.1186/1471-2288-11-77 21605357
49 National Toxicology Program (NTP). DART-01: Growth and clinical finding tables (I), pathology tables (PA), developmental and reproductive tables (R) from NTP developmental and reproductive toxicity studies. Research Triangle Park, NC. 2019. 10.22427/NTP-DATA-DART-01
50 Marklund A Andersson B Haglund P Screening of organophosphorus compounds and their distribution in various indoor environments. Chemosphere. 2003; 53(9):1137–1146. 10.1016/S0045-6535(03)00666-0 14512118
51 Slotkin TA Levin ED Seidler FJ Developmental neurotoxicity of parathion: progressive effects on serotonergic systems in adolescence and adulthood. Neurotoxicol Teratol. 2009; 31(1):11–17. 10.1016/j.ntt.2008.08.004 18773955
52 Slotkin TA Seidler FJ Developmental exposure to organophosphates triggers transcriptional changes in genes associated with Parkinson’s disease in vitro and in vivo. Brain Res Bull. 2011; 86(5-6):340–347. 10.1016/j.brainresbull.2011.09.017 21968025
53 Muñoz-Quezada MT Lucero BA Barr DB Steenland K Levy K Ryan PB Iglesias V Alvarado S Concha C Rojas E Neurodevelopmental effects in children associated with exposure to organophosphate pesticides: A systematic review. Neurotoxicology. 2013; 39:158–168. 10.1016/j.neuro.2013.09.003 24121005
54 Carr RL Graves CA Mangum LC Nail CA Ross MK Low level chlorpyrifos exposure increases anandamide accumulation in juvenile rat brain in the absence of brain cholinesterase inhibition. Neurotoxicology. 2014;43:82–89. 10.1016/j.neuro.2013.12.009 24373905
55 Dishaw LV Powers CM Ryde IT Roberts SC Seidler FJ Slotkin TA Stapleton HM Is the PentaBDE replacement, tris (1, 3-dichloro-2-propyl) phosphate (TDCPP), a developmental neurotoxicant? Studies in PC12 cells. Toxicol Appl Pharmacol. 2011; 256(3):281–289. 10.1016/j.taap.2011.01.005 21255595
56 Behl M Hsieh J-H Shafer TJ Mundy WR Rice JR Boyd WA Freedman JH Hunter Iii ES Jarema KA Padilla S Use of alternative assays to identify and prioritize organophosphorus flame retardants for potential developmental and neurotoxicity. Neurotoxicol Teratol. 2015; 52:181–193. 10.1016/j.ntt.2015.09.003 26386178
57 Dishaw LV Hunter DL Padnos B Padilla S Stapleton HM Developmental exposure to organophosphate flame retardants elicits overt toxicity and alters behavior in early life stage zebrafish (Danio rerio). Toxicol Sci. 2014; 142(2):445–454. 10.1093/toxsci/kfu194 25239634
58 Oliveri AN Bailey JM Levin ED Developmental exposure to organophosphate flame retardants causes behavioral effects in larval and adult zebrafish. Neurotoxicol Teratol. 2015; 52:220–227. 10.1016/j.ntt.2015.08.008 26344674
59 Behl M Rice JR Smith MV Co CA Bridge MF Hsieh J-H Freedman JH Boyd WA Editor’s highlight: comparative toxicity of organophosphate flame retardants and polybrominated diphenyl ethers to Caenorhabditis elegans. Toxicol Sci. 2016; 154(2):241–252. 10.1093/toxsci/kfw162 27566445
60 Xu T Li P Wu S Lei L He D Tris (2-chloroethyl) phosphate (TCEP) and tris (2-chloropropyl) phosphate (TCPP) induce locomotor deficits and dopaminergic degeneration in Caenorhabditis elegans. Toxicol Res (Camb). 2017; 6(1):63–72. 10.1039/C6TX00306K 30090477
61 Hall AP Elcombe CR Foster JR Harada T Kaufmann W Knippel A Küttler K Malarkey DE Maronpot RR Nishikawa A Liver hypertrophy: A review of adaptive (adverse and non-adverse) changes—conclusions from the 3rd International ESTP Expert Workshop. Toxicol Pathol. 2012; 40(7):971–994. 10.1177/0192623312448935 22723046
62 Maronpot RR Yoshizawa K Nyska A Harada T Flake G Mueller G Singh B Ward JM Hepatic enzyme induction: histopathology. Toxicol Pathol. 2010; 38(5):776–795. 10.1177/0192623310373778 20585142
63 Carmichael NG Enzmann H Pate I Waechter F The significance of mouse liver tumor formation for carcinogenic risk assessment: results and conclusions from a survey of ten years of testing by the agrochemical industry. Environ Health Perspect. 1997; 105(11):1196–1203. 10.1289/ehp.971051196 9370513
64 Wickramaratne GA The post‐natal fate of supernumerary ribs in rat teratogenicity studies. J Appl Toxicol. 1988; 8(2):91–94. 10.1002/jat.2550080205 3379236
65 Foulon O, Jaussely C, Repetto M, Urtizberea M, Blacker AM. Postnatal evolution of supernumerary ribs in rats after a single administration of sodium salicylate. J Appl Toxicol. 2000; 20(3):205-209. 10.1002/(SICI)1099-1263(200005/06)20:3<205:AID-JAT635>3.0.CO;2-G
66 Spectrum A The Aldrich Library of Infrared Spectra. 3rd ed. Milwaukee (WI): Aldrich Chemical Company, Inc; 1981. p. 1578.