# Conclusions

Under the conditions of this prenatal study, no evidence of developmental toxicity of TCPP was found in Hsd:Sprague Dawley^®^ SD^®^ rats administered 162.5, 325, or 650 mg/kg/day in the absence of overt maternal toxicity.