# Discussion

Tris(chloropropyl) phosphate (TCPP) is a high production flame retardant mixture for use in textiles, furniture (flexible polyurethane foam), construction materials (rigid polyurethane foam), electronic products, paints, coatings, and adhesives.^2,50^ TCPP has been proposed as a substitute for brominated flame retardants and as a replacement for other chlorinated flame retardants such as tris(2-chloroethyl) phosphate that have been identified to be toxic.^8,9^ Based on the potential for increased use and exposure, the Consumer Product Safety Commission nominated TCPP for toxicological testing by NTP. NTP is in the process of evaluating TCPP toxicity on various cellular or molecular targets in vitro and is testing for subchronic toxicity, chronic toxicity, carcinogenicity, genotoxicity, and immunotoxicity in rodent models. Further information on NTP’s evaluation of the potential toxicity of TCPP is available at the Program’s website.^1^ The purpose of this report is to summarize and discuss TCPP effects on prenatal development in rats because of concerns for exposure to women of childbearing potential and the lack of robust evaluations for developmental toxicity. This DART Technical Report presents the findings of the dose range-finding and prenatal developmental toxicity studies of TCPP in Hsd:Sprague Dawley^®^ SD^®^ rats.

TCPP doses selected for the range-finding study were 0, 300, 650, 1,000 mg/kg. Maternal toxicity was observed, as evidenced by mortality and morbidity in 7 of 11 dams in the 1,000 mg/kg group. In previously conducted studies, TCPP did not affect survival of Wistar Han rats exposed to as much as 1,000 mg TCPP/kg body weight per day in the diet over two generations.^3,5^ TCPP also did not affect survival in a developmental toxicity study of Wistar rats given TCPP in their diet (up to 893 mg/kg per day).^3,16^ These data suggest the route of administration of TCPP could have contributed to maternal toxicity observed in the current range-finding study. Other differences in the exposure paradigms such as exposure duration and strain differences may also have contributed to toxicity.

In this dose range-finding study, treatment-related clinical observations are reported in dams exposed to 1,000 mg/kg TCPP. These included convulsions, tremors, prone, gasping, hypoactivity, hunched posture, nasal discharge, stained fur, piloerection, salivation, and rooting (pre- and postdosing), which occurred throughout gestation. One dam in the 650 mg/kg dose range-finding study was euthanized moribund following adverse clinical observations including ataxia, hypoactivity, piloerection, labored respiration, pale and cold to touch. Because of the singular incidence of overt toxicity and adverse clinical observations in the 650 mg/kg group, the relationship between TCPP exposure and maternal toxicity at this dose was considered uncertain. These findings are consistent with reported clinical observations from acute oral (gavage) toxicity studies, which are summarized in the European Union Risk Assessment Report of TCPP.^5^

Several clinical observations (e.g., convulsions, tremors) observed in the dose range-finding study indicate that high doses of TCPP may be neurotoxic in rats. TCPP belongs to the flame retardant class of organophosphate flame retardants, which are structurally similar to organophosphate pesticides, many of which have previously been shown to affect the nervous system.^51-54^ In vitro studies in neuronal cells suggest that flame retardants with an organophosphate backbone (i.e., organophosphate flame retardants) may be toxic to adult and developing nervous systems,^55,56^ developing zebrafish,^57,58^ and Caenorhabditis elegans.^59,60^ However, the clinical observations of neurotoxicity observed in the range-finding study were not observed in a rodent developmental toxicity study in the published literature,^16^ possibly due to TCPP administration through feed. Likewise, clinical signs of neurotoxicity were not observed in several repeat dose or reproduction feed studies summarized by risk assessment documents or reported in the literature.^1,3,5,11^ These data suggest that neurological clinical observations are limited to instances of high bolus doses of TCPP.

The dose range-finding study results demonstrating overt maternal toxicity (i.e., mortality) at 1,000 mg/kg informed the selection of the TCPP doses for this prenatal developmental toxicity study, which were 0, 162.5, 325, or 650 mg/kg/day As predicted, TCPP was well tolerated at all administered doses during the study, which allowed for definitive evaluation of TCPP effects on embryo-fetal development. No significant effects were observed on maternal survival, body weights, or feed consumption in the prenatal developmental toxicity study of TCPP. Also as anticipated, hyperactivity was observed in one 650 mg/kg dam, but not in dams exposed to lower doses. This clinical observation occurred from GD 7 to GD 13 and was considered treatment related. The clinical observations were also similar to those made in the range-finding study, which supports a dose-related effect of TCPP exposure. At necropsy, several organ weights were evaluated and dose-related increases in absolute and relative liver weights were found. Multiple studies have shown that TCPP exposure can increase liver weights and alter liver histopathology in rats and mice following repeat exposures.^3-5,19^ Therefore, these results are concordant with previous research and confirm that the liver is a target following TCPP exposure in vivo. Whether chemical-induced changes in liver weights are adverse or adaptive has been debated in the literature and typically includes review of liver histopathology and enzyme induction (ref).^61,62^ In this study, all information required to determine if a 26% increase in dam relative liver weight is toxicologically relevant is not available; however, some studies suggest that a 50% increase in liver weight is correlated with adverse changes such as tumor induction (ref).^63^ The information available suggested that the dose-related increase in liver weight was deemed an adaptive change rather than representative of overt toxicity in the dams in this study.

Because of excess maternal toxicity in the 1,000 mg/kg group of the dose range-finding study, assessment of developmental toxicity was not possible at this dose. There were some indications of TCPP-related fetal effects in the 650 mg/kg group, but these findings were either not statistically significant (increased mean percent postimplantation loss, decreased number of live fetuses per litter, and decreased gravid uterine weight) or of no biological significance due to the magnitude of the effect (i.e., decreased mean fetal body weight per litter). Increasing the number of animals examined from 11 to 25 for the prenatal developmental toxicity study confirmed that TCPP exposure during gestation has no significant effect on embryo-fetal toxicity. Overall, there was no evidence of growth retardation following TCPP exposure.

Examination of fetuses for malformations or variations in the prenatal developmental toxicity study demonstrated that TCPP exposure does not cause toxicologically significant external, visceral, or skeletal defects. The only statistically significant exposure-related finding was an increase in the percentage of fetuses with lumbar rudimentary ribs. In NTP’s experience, this skeletal variation is variable among this strain of rat. Rudimentary ribs have been reported to be common in laboratory rodents and are considered reversible and of limited toxicological relevance.^64,65^

In the previously published developmental toxicity study in rats,^16^ dose-related increases in the incidences of cervical ribs and absent 13th rib malformations were reported. TCPP exposure in the study by Kawasaki et al.^16^ occurred in feed from GD 0 to GD 20 and was conducted in Wistar rats. These experimental variables (exposure window, route of administration, and rodent strain) may account for the differences in skeletal malformations observed between the Kawasaki et al.^16^ report and the prenatal developmental toxicity study described here.