# Results

## Data Availability

NTP evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://dx.doi.org/10.22427/NTP-DATA-DART-01.^49^

## Dose Range-finding Study in Rats

### Maternal Findings

#### Viability and Clinical Observations

Seven of 11 dams in the 1,000 mg/kg group were either found dead or euthanized moribund (Table 4). Associated adverse neurological clinical observations in the 1,000 mg/kg group included convulsions, tremors, and hypoactivity. Additional observations included gasping, hunched posture, nasal discharge, stained fur, piloerection, prone, salivation, and rooting (pre- and postdosing), which occurred throughout the gestational period (Appendix E^49^). One female was euthanized moribund in the 650 mg/kg group on gestation day (GD) 16 with clinical observations including cold to touch, hypoactivity, paleness, ataxia, and labored breathing. All vehicle control (0 mg/kg) and 300 mg/kg animals survived to study termination and showed no treatment-related clinical observations.

Table 4 Maternal Disposition of Rats in the Dose Range-finding Gavage Study of Tris(chloropropyl) Phosphate

| 0 mg/kg | 300 mg/kg | 650 mg/kg | 1,000 mg/kg
Time-mated Females | 11 | 11 | 11 | 11
Pregnant (on GD 21) | 10 | 11 | 7 | 4
Euthanasia Moribund – Pregnant | 0 | 0 | 1^a^ | 5^b^
Found Dead – Pregnant | 0 | 0 | 0 | 1^c^
Nonpregnant (on GD 21) | 1 | 0 | 3 | 0
Found Dead – Nonpregnant | 0 | 0 | 0 | 1^d^

GD = gestation day.

^a^ Dam removed on GD 16.

^b^ Dams removed on GD 6, GD 13, and GD 20 (3).

^c^ Dam found dead on GD 13.

^d^ Dam found dead on GD 6.

#### Body Weights and Feed Consumption

Maternal body weight gain from GD 9 to GD 12 was 26% lower in the 1,000 mg/kg group relative to the vehicle control group (Table 5). Maternal body weight gain from GD 6 to GD 21 in the 1,000 mg/kg group, however, was similar to that in the vehicle control group. Overall, no dose-related effects on maternal body weight gain during gestation were found (Figure 2; Table 5 and Appendix E^49^).

Table 5 Summary of Maternal Body Weight Gains of Rats in the Dose Range-finding Gavage Study of Tris(chloropropyl) Phosphate

Gestation Day Interval | 0 mg/kg | 300 mg/kg | 650 mg/kg | 1,000 mg/kg
6–21 | 136.1 ± 2.6^a^ (10) | 138.4 ± 4.3 (11) | 127.5 ± 17.1 (7) | 130.2 ± 12.7 (4)
3–6 | 16.5 ± 2.5 (10) | 14.8 ± 2.3 (11) | 13.0 ± 1.1 (8) | 10.8 ± 1.2 (10)
6–9 | 11.4 ± 0.4 (10) | 12.8 ± 1.1 (11) | 15.1 ± 1.3 (8) | 12.1 ± 1.8 (9)
9–12 | 18.5 ± 1.1* (10) | 15.8 ± 0.8 (11) | 16.1 ± 0.9 (8) | 13.8 ± 1.5* (9)
12–15 | 19.3 ± 0.9 (10) | 18.1 ± 0.9 (11) | 17.7 ± 1.9 (8) | 17.4 ± 2.5 (7)
15–18 | 38.9 ± 1.7 (10) | 41.6 ± 1.9 (11) | 30.5 ± 9.8 (7) | 39.3 ± 3.4 (7)
18–21 | 48.1 ± 0.8 (10) | 50.1 ± 2.0 (11) | 46.8 ± 4.4 (7) | 47.0 ± 7.4 (4)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Williams or Dunnett test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

^a^ Body weight gains for pregnant females are given in grams. Data are displayed as mean ± standard error. Number of dams weighed is given in parentheses.

Figure 2

Maternal Growth Curves for Pregnant Rats Administered Tris(chloropropyl) Phosphate by Gavage in the Dose Range-finding Study

Information for statistical significance in maternal weights is provided in Table 5 and Appendix E.^49^

In association with transient body weight changes, maternal feed consumption was 19% (GD 6 to GD 9) and 12% (GD 9 to GD 12) lower in the 1,000 mg/kg group relative to vehicle controls for those time periods (Table 6). Feed consumption from GD 6 to GD 21 by the 1,000 mg/kg group, however, was similar to that in the vehicle control group. Feed consumption in the 300 and 650 mg/kg groups was similar to that in the vehicle control group (Table 6).

Table 6 Summary of Maternal Feed Consumption of Rats in the Dose Range-finding Gavage Study of Tris(chloropropyl) Phosphate

Gestation Day Interval | 0 mg/kg | 300 mg/kg | 650 mg/kg | 1,000 mg/kg
6–21 | 21.8 ± 0.46^a^ (10) | 21.4 ± 0.44 (11) | 21.8 ± 1.21 (7) | 21.4 ± 0.76 (4)
3–6 | 19.8 ± 0.54 (10) | 19.5 ± 0.42 (11) | 19.6 ± 0.55 (8) | 19.0 ± 0.55 (10)
6–9 | 19.5 ± 0.53** (10) | 17.8 ± 0.51 (11) | 17.9 ± 0.86 (8) | 15.9 ± 0.71** (9)
9–12 | 20.6 ± 0.43** (10) | 19.6 ± 0.48 (11) | 19.6 ± 0.47 (8) | 18.2 ± 0.69** (9)
12–15 | 20.9 ± 0.52 (10) | 20.9 ± 0.34 (11) | 21.9 ± 0.57 (8) | 21.0 ± 0.79 (7)
15–18 | 24.1 ± 0.63 (10) | 23.6 ± 0.62 (11) | 24.7 ± 1.71 (7) | 24.9 ± 0.62 (7)
18–21 | 23.9 ± 0.54* (10) | 25.1 ± 0.62 (11) | 24.5 ± 2.79 (7) | 26.5 ± 1.07 (4)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Shirley or Dunn test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Feed consumption data for pregnant females are given in grams/day. Data are displayed as mean ± standard error. Number of dams with feed consumption measured is given in parentheses.

#### Maternal and Litter Observations

The maternal toxicity observed in the 1,000 mg/kg TCPP dose group resulted in only 4 litters available for assessments, as compared to 7 to 11 litters in the other groups (Table 7). This dose group had fewer implants per female; however, this is a variable endpoint in this strain and because TCPP dosing began on GD 6, this finding is not considered related to treatment. Also, the number of live male fetuses per litter in the 1,000 mg/kg group was significantly lower (by 53%) compared to vehicle controls. Additional observations included nonsignificant decreases in the number of live fetuses per litter and mean gravid uterine weight in the 650 and 1,000 mg/kg groups. These findings were considered to have an uncertain relationship to TCPP exposure because of the small sample size and number of litters available for evaluation. Overall, TCPP exposure had no significant effects on embryo-fetal survival (i.e., postimplantation loss) or growth retardation (i.e., fetal weight).

Table 7 Summary of Uterine Content Data for Rats in the Dose Range-finding Gavage Study of Tris(chloropropyl) Phosphate

| 0 mg/kg | 300 mg/kg | 650 mg/kg | 1,000 mg/kg
Pregnancy Summary
Mated females | 11 | 11 | 11 | 11
Pregnant females | 10 | 11 | 8 | 10
Pregnant females examined on GD 21^a^ | 10** | 11 | 7 | 4*
Corpora lutea per female^b^ | 16.90 ± 0.66 (10) | 15.55 ± 0.77 (11) | 16.14 ± 1.37 (7) | 16.25 ± 0.48 (4)
Implantations per female^b^ | 13.90 ± 0.62 (10) | 13.45 ± 0.53 (11) | 12.43 ± 1.21 (7) | 10.75 ± 2.59 (4)
Percent postimplantation loss^b^ | 2.14 ± 2.14 (10) | 0.83 ± 0.83 (11) | 6.46 ± 3.99 (7) | 1.92 ± 1.92 (4)
Total resorptions per litter^b^ | 0.30 ± 0.30 (10) | 0.09 ± 0.09 (11) | 0.29 ± 0.18 (7) | 0.25 ± 0.25 (4)
Early resorptions per litter^b^ | 0.30 ± 0.30 (10) | 0.09 ± 0.09 (11) | 0.29 ± 0.18 (7) | 0.25 ± 0.25 (4)
Late resorptions per litter^b^ | 0.00 ± 0.00 (10) | 0.00 ± 0.00 (11) | 0.00 ± 0.00 (7) | 0.00 ± 0.00 (4)
Dead fetuses per litter^b^ | 0.00 ± 0.00 (10) | 0.00 ± 0.00 (11) | 0.00 ± 0.00 (7) | 0.00 ± 0.00 (4)
Number of early resorptions^c^ | 3 | 1 | 2 | 1
Number of late resorptions | 0 | 0 | 0 | 0
Number of whole litter resorptions^a^ | 0 | 0 | 0 | 0
Number of dead fetuses | 0 | 0 | 0 | 0
Live Fetuses^b^
Number of live fetuses | 136 | 147 | 83 | 42
Live fetuses per litter | 13.60 ± 0.69 (10) | 13.36 ± 0.58 (11) | 11.86 ± 1.44 (7) | 10.50 ± 2.53 (4)
Live male fetuses per litter | 7.44 ± 0.56* (9)^d^ | 6.64 ± 0.59 (11) | 5.57 ± 1.02 (7) | 3.50 ± 0.87** (4)
Live female fetuses per litter | 6.11 ± 0.48 (9)^d^ | 6.73 ± 0.66 (11) | 6.29 ± 0.87 (7) | 7.00 ± 2.16 (4)
Percent live male fetuses per litter | 54.95 ± 2.48 (9)^d^ | 49.91 ± 4.20 (11) | 46.53 ± 6.43 (7) | 39.81 ± 10.48 (4)
Fetal Weight (g)^d^
Fetal weight per litter | 5.13 ± 0.06 (9)^e^ | 5.24 ± 0.09 (11) | 5.20 ± 0.10 (7) | 5.23 ± 0.22 (4)
Male weight per litter | 5.23 ± 0.07 (9)^e^ | 5.42 ± 0.07 (11) | 5.33 ± 0.15 (7) | 5.44 ± 0.21 (4)
Female weight per litter | 5.01 ± 0.07 (9)^e^ | 5.07 ± 0.09 (11) | 5.15 ± 0.09 (7) | 5.06 ± 0.14 (4)
Gravid Uterine Weight (g)^f^
Gravid uterine weight | 98.11 ± 4.01 (10) | 96.62 ± 3.35 (11) | 86.37 ± 9.78 (7) | 74.65 ± 15.90 (4)
Terminal body weight | 378.7 ± 5.7 (10) | 376.4 ± 6.3 (11) | 363.9 ± 20.4 (7) | 365.0 ± 10.1 (4)
Adjusted body weight | 280.62 ± 4.86 (10) | 279.76 ± 4.06 (11) | 277.54 ± 11.58 (7) | 290.35 ± 11.08 (4)

Values are reported per litter as mean ± standard error (n) and do not include nonpregnant females or those that did not survive to end of study.

GD = gestation day.

* Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column).

** p ≤ 0.01.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ No statistical analyses were performed on the number of early resorptions.

^d^ Statistical analysis performed using a mixed-effects linear model with litter as a random effect (trend and pairwise).

^e^ n = 9 litters: Individual sex and fetal body weight data for 14 fetuses were inadvertently not collected for one litter.

^f^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests; adjusted body weight = terminal body weight minus gravid uterine weight.

### Fetal Findings

#### External

No exposure-related external malformations or variations were attributed to TCPP administration at 300, 650, or 1,000 mg/kg (Appendix E^49^).

### Dose Selection Rationale for the Prenatal Developmental Toxicity Study in Rats

Excessive maternal toxicity (animals were euthanized moribund or found dead) in the dose range-finding study was observed at 1,000 mg/kg. At 650 mg/kg, an uncertain relationship between TCPP administration and toxicity was found because of the presence of a single moribund dam with adverse clinical observations. No toxicity was observed at lower doses. Thus, dose concentrations of 0, 162.5, 325, or 650 mg/kg were chosen for the subsequent prenatal developmental toxicity gavage study.

## Prenatal Developmental Toxicity Study in Rats

### Maternal Findings

#### Viability and Clinical Observations

No animals were removed from the study prior to scheduled necropsy (Table 8). Dose-related clinical observations were observed in six females in the 650 mg/kg group and included nasal discharge, salivation, twitches, ataxia, piloerection, audible respiratory sounds, and hyperactivity (Appendix E^49^). The duration for most of the clinical observations was limited to 1 day of gestation aside from hyperactivity in one female, which was observed over a 7-day period starting on GD 7. No dose-related clinical effects were observed in the other TCPP groups or in the vehicle control (0 mg/kg) animals.

Table 8 Maternal Disposition of Rats in the Prenatal Developmental Toxicity Gavage Study of Tris(chloropropyl) Phosphate

| 0 mg/kg^a^ | 162.5 mg/kg | 325 mg/kg | 650 mg/kg
Time-mated Females | 50 | 25 | 25 | 25
Pregnant (on GD 21) | 44 | 21 | 21 | 20
Nonpregnant (on GD 21) | 6 | 4 | 4 | 5

GD = gestation day.

^a^ This study had two vehicle control groups. Data from both vehicle control groups were combined and are presented here.

#### Body Weights and Feed Consumption

No dose-related effects on maternal body weight gain during gestation were found in any dose group (Figure 3 and Table 9). Daily mean body weights for dams in each dose group are available in Appendix E.^49^ Compared to the vehicle control group, maternal feed consumption was 8–16% lower over GD 6 to GD 9 and GD 9 to GD 12 for dams in the 650 mg/kg group (Table 10). The feed consumption differences were transient, and, overall, TCPP administration had no effect on maternal feed consumption during gestation (Table 10).

Figure 3

Maternal Growth Curves for Pregnant Rats Administered Tris(chloropropyl) Phosphate by Gavage in the Prenatal Developmental Toxicity Study

Information for statistical significance in maternal weights is provided in Table 9 and Appendix E.^49^

Table 9 Summary of Maternal Body Weight Gains of Rats in the Prenatal Developmental Toxicity Gavage Study of Tris(chloropropyl) Phosphate

Gestation Day Interval | 0 mg/kg | 162.5 mg/kg | 325 mg/kg | 650 mg/kg
6–21 | 139.6 ± 2.5^a^ (44) | 143.6 ± 3.0 (21) | 139.9 ± 3.8 (21) | 137.6 ± 6.3 (20)
3–6 | 14.4 ± 0.8 (44) | 14.1 ± 0.7 (21) | 15.7 ± 1.0 (21) | 14.1 ± 1.0 (20)
6–9 | 12.9 ± 0.6 (44) | 13.0 ± 0.6 (21) | 12.5 ± 0.8 (21) | 10.6 ± 0.8 (20)
9–12 | 16.8 ± 0.6 (44) | 15.5 ± 1.1 (21) | 16.8 ± 0.8 (21) | 15.4 ± 1.2 (20)
12–15 | 18.9 ± 0.9 (44) | 20.5 ± 0.9 (21) | 19.6 ± 1.4 (21) | 21.2 ± 1.3 (20)
15–18 | 42.4 ± 1.0 (44) | 43.7 ± 1.0 (21) | 41.9 ± 1.6 (21) | 39.0 ± 2.2 (20)
18–21 | 48.8 ± 1.4 (44) | 50.8 ± 1.5 (21) | 49.0 ± 1.8 (21) | 51.4 ± 3.1 (20)

Statistical analysis performed by the Jonckheere test (trend) or the Williams or Dunnett test (pairwise comparison) found no statistically significant trend or pairwise comparison.

^a^ Body weight gains for pregnant females are given in grams. Data are displayed as mean ± standard error. Number of dams weighed is given in parentheses.

Table 10 Summary of Maternal Feed Consumption of Rats in the Prenatal Developmental Toxicity Gavage Study of Tris(chloropropyl) Phosphate

Gestation Day Interval | 0 mg/kg | 162.5 mg/kg | 325 mg/kg | 650 mg/kg
6–21 | 22.8 ± 0.23^a^ (44) | 22.5 ± 0.33 (21) | 22.9 ± 0.33 (21) | 22.2 ± 0.42 (20)
3–6 | 20.2 ± 0.42 (44) | 18.7 ± 0.24 (21) | 19.7 ± 0.50 (21) | 19.4 ± 0.55 (20)
6–9 | 20.4 ± 0.32** (44) | 19.4 ± 0.37 (21) | 18.8 ± 0.41** (21) | 17.0 ± 0.46** (20)
9–12 | 21.6 ± 0.34** (44) | 20.7 ± 0.41 (21) | 21.0 ± 0.38 (21) | 19.8 ± 0.54** (20)
12–15 | 21.6 ± 0.22 (44) | 21.1 ± 0.37 (21) | 22.4 ± 0.55 (21) | 21.4 ± 0.29 (20)
15–18 | 24.8 ± 0.34 (44) | 25.0 ± 0.42 (21) | 25.5 ± 0.53 (21) | 25.2 ± 0.74 (20)
18–21 | 25.5 ± 0.36** (44) | 26.3 ± 0.51 (21) | 27.0 ± 0.38* (21) | 27.8 ± 0.66** (20)

* Statistically significant (p ≤ 0.05) trend (by the Jonckheere test) or pairwise comparison (by the Shirley or Dunn test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

** p ≤ 0.01.

^a^ Feed consumption for pregnant females is given in grams per day. Data are displayed as mean ± standard error. Number of dams with feed consumption measured is given in parentheses.

### Maternal and Litter Observations

There were no maternal gross observations at necropsy (Appendix E^49^). However, there were dose-related increases in absolute (9%, 16%, and 26% at 162.5, 325, and 650 mg/kg, respectively) and relative liver weights (Table 11).

Table 11 Summary of Maternal Liver Weights and Liver Weight Ratios for Rats in the Prenatal Developmental Toxicity Gavage Study of Tris(chloropropyl) Phosphate^a^

| 0 mg/kg | 162.5 mg/kg | 325 mg/kg | 650 mg/kg
n | 44 | 21 | 21 | 20
Necropsy Body Wt. | 378.5 ± 3.0 | 382.7 ± 4.0 | 383.1 ± 5.2 | 375.2 ± 8.3
Liver
Absolute | 14.35 ± 0.19** | 15.62 ± 0.32** | 16.58 ± 0.27** | 18.02 ± 0.56**
Relative | 37.93 ± 0.41** | 40.78 ± 0.67** | 43.39 ± 0.78** | 48.09 ± 1.09**

** Statistically significant (p ≤ 0.01) trend (by the Jonckheere test) or pairwise comparison (by the Williams or Dunnett test). A significant trend test is indicated in the vehicle control column. A significant pairwise comparison with the vehicle control group is indicated in the dose group column.

^a^ Liver weights (absolute weights) and body weights are given in grams; liver weight-to-body weight ratios (relative weights) are given as mg organ weight/g body weight. Data are displayed as mean ± standard error.

There were no effects on pregnancy status or litter size following TCPP administration (Table 12). Although a twofold increase in mean percent postimplantation loss in the 650 mg/kg group as compared to the vehicle controls was found, this increase is the result of one dam that had nine early resorptions. Given the singular litter incidence, this finding in the 650 mg/kg group was not considered related to TCPP administration. The number of live fetuses per litter was 5% lower in the 325 and 650 mg/kg groups and was accompanied by lower gravid uterine weights (<7%) at these doses; however, these differences were not statistically significant. No exposure-related effects on absolute fetal body weights (male or female) were evident.

Table 12 Summary of Uterine Content Data for Rats in the Prenatal Developmental Toxicity Gavage Study of Tris(chloropropyl) Phosphate

| 0 mg/kg | 162.5 mg/kg | 325 mg/kg | 650 mg/kg
Pregnancy Summary
Mated females | 50 | 25 | 25 | 25
Pregnant females | 44 | 21 | 21 | 20
Pregnant females examined on GD 21^a^ | 44 | 21 | 21 | 20
Corpora lutea per female | 16.64 ± 0.37 (44) | 18.05 ± 0.55 (21) | 16.62 ± 0.72 (21) | 17.55 ± 0.85 (20)
Implantations per female | 14.18 ± 0.29 (44) | 14.81 ± 0.38 (21) | 13.48 ± 0.65 (21) | 13.70 ± 0.67 (20)
Percent postimplantation loss^b^ | 3.81 ± 1.13 (44) | 3.42 ± 0.99 (21) | 4.33 ± 1.19 (21) | 7.17 ± 4.50 (20)
Total resorptions per litter^b^ | 0.55 ± 0.16 (44) | 0.52 ± 0.15 (21) | 0.52 ± 0.15 (21) | 0.75 ± 0.45 (20)
Early resorptions per litter^b^ | 0.50 ± 0.16 (44) | 0.52 ± 0.15 (21) | 0.52 ± 0.15 (21) | 0.75 ± 0.45 (20)
Late resorptions per litter^b^ | 0.05 ± 0.03 (44) | 0.00 ± 0.00 (21) | 0.00 ± 0.00 (21) | 0.00 ± 0.00 (20)
Dead fetuses per litter^b^ | 0.02 ± 0.02 (44) | 0.00 ± 0.00 (21) | 0.10 ± 0.07 (21) | 0.00 ± 0.00 (20)
Number of early resorptions^c^ | 22 | 11 | 11 | 15
Number of late resorptions^c^ | 2 | 0 | 0 | 0
Number of whole litter resorptions^a^ | 0 | 0 | 0 | 0
Number of dead fetuses^c^ | 1 | 0 | 2 | 0
Live Fetuses^b^
Number of live fetuses | 599 | 300 | 270 | 259
Live fetuses per litter | 13.61 ± 0.30 (44) | 14.29 ± 0.37 (21) | 12.86 ± 0.62 (21) | 12.95 ± 0.91 (20)
Live male fetuses per litter | 6.48 ± 0.28 (44) | 7.57 ± 0.41 (21) | 6.71 ± 0.54 (21) | 6.60 ± 0.54 (20)
Live female fetuses per litter | 7.14 ± 0.30 (44) | 6.71 ± 0.52 (21) | 6.10 ± 0.46 (21) | 6.35 ± 0.66 (20)
Percent live male fetuses per litter | 47.71 ± 1.88 (44) | 53.48 ± 3.05 (21) | 50.51 ± 3.79 (21) | 50.04 ± 3.96 (20)
Fetal Weight (g)^d^
Fetal weight per litter | 5.29 ± 0.04 (44) | 5.22 ± 0.06 (21) | 5.42 ± 0.08 (21) | 5.22 ± 0.07 (20)
Male fetal weight per litter | 5.42 ± 0.05 (44) | 5.35 ± 0.06 (21) | 5.47 ± 0.06 (20) | 5.34 ± 0.06 (19)
Female fetal weight per litter | 5.17 ± 0.04 (44) | 5.08 ± 0.06 (21) | 5.30 ± 0.09 (21) | 5.09 ± 0.07 (20)
Gravid Uterine Weight (g)^e^
Gravid uterine weight | 98.89 ± 1.93 (44) | 101.98 ± 2.23 (21) | 95.76 ± 4.06 (21) | 91.78 ± 5.91 (20)
Terminal body weight | 378.5 ± 3.0 (44) | 382.7 ± 4.0 (21) | 383.1 ± 5.2 (21) | 375.2 ± 8.3 (20)
Adjusted body weight | 279.56 ± 1.81 (44) | 280.75 ± 2.23 (21) | 287.30 ± 2.38 (21) | 283.45 ± 3.85 (20)

Values are reported per litter as mean ± standard error (n) and do not include nonpregnant females or those that did not survive to end of study.

GD = gestation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ No statistical analyses were performed on the number of early resorptions, number of late resorptions, or number of dead fetuses.

^d^ Statistical analysis performed using a mixed-effects linear model with litter as a random effect (trend and pairwise).

^e^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests; adjusted body weight = terminal body weight minus gravid uterine weight.

### Fetal Findings

#### External

In the external exam, various low or single-incidence findings were observed in the head and placenta that were considered unrelated to exposure. The only malformation, a meningoencephalocele in the 162.5 mg/kg group, was also considered unrelated to TCPP exposure because of the single incidence and lack of a dose response (Appendix E^49^).

#### Visceral

Malformations and associated variations were observed in the ureter, which included hydroureter malformations (bilateral and unilateral) in the vehicle control and 325 mg/kg groups and distention of the ureter (bilateral and unilateral) across all groups. Although associated, these findings were not considered exposure related because the incidences of findings in groups exposed to TCPP were either similar to or lower than the incidences in vehicle control animals. Various other single-incidence malformations and variations were observed in the abdomen, heart, and thorax following the visceral exam; these findings were either not considered exposure related or observed only in vehicle control animals. Overall, there were no effects of TCPP exposure on the incidences of fetal visceral abnormalities (Table 13; Appendix E^49^).

Table 13 Summary of Selected Fetal Visceral Findings in Rats in the Prenatal Developmental Toxicity Gavage Study of Tris(chloropropyl) Phosphate

| 0 mg/kg | 162.5 mg/kg | 325 mg/kg | 650 mg/kg
Total Number of Fetuses | 599 | 300 | 270 | 259
Number of Fetuses Examined | 599 | 299 | 270 | 259
Number of Litters Examined | 44 | 21 | 21 | 20
Pelvis
Ureter
Total, hydroureter – [M]
Fetuses | 1 (0.17) | 0 (0.00) | 1 (0.37) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 1 (4.76) | 0 (0.00)
Bilateral, hydroureter – [M]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Left, hydroureter – [M]
Fetuses | 0 (0.00) | 0 (0.00) | 1 (0.37) | 0 (0.00)
Litters | 0 (0.00) | 0 (0.00) | 1 (4.76) | 0 (0.00)
Total, distended – [V]
Fetuses | 92 (15.36)**^#^ | 35 (11.71) | 14 (5.19)**^##^ | 24 (9.27)**
Litters | 30 (68.18) | 15 (71.43) | 5 (23.81)** | 12 (60.00)
Bilateral, distended – [V]
Fetuses | 47 (7.85)**^#^ | 14 (4.68)* | 7 (2.59)**^#^ | 10 (3.86)*
Litters | 19 (43.18) | 10 (47.62) | 3 (14.29)* | 6 (30.00)
Left, distended – [V]
Fetuses | 22 (3.67) | 9 (3.01) | 4 (1.48) | 9 (3.47)
Litters | 16 (36.36) | 8 (38.10) | 3 (14.29) | 7 (35.00)
Right, distended – [V]
Fetuses | 23 (3.84)* | 12 (4.01) | 3 (1.11)*^#^ | 5 (1.93)
Litters | 15 (34.09) | 4 (19.05) | 1 (4.76)** | 4 (20.00)

Upper row denotes number of affected fetuses and (%) and lower row the number of affected litters and (%).

Statistical analysis for litter data and for fetal data (without the litter effects) performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

* Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column).

** p ≤ 0.01.

Statistical analysis of fetuses with litter-based adjustments performed by mixed-effects logistic regression.

^#^ Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column) in litter-based analysis of fetuses.

^##^ p ≤ 0.01.

[M] = malformation; [V] = variation.

#### Head

Single incidences of malformations occurred in the head soft tissue including enlarged nasal sinus, anophthalmia, and folded retina that were noted in vehicle control animals and groups exposed to TCPP (Appendix E^49^). The only variation, enlarged lateral ventricle of the brain, was observed in the same fetus with anophthalmia and meningoencephalocele in the 162.5 mg/kg group. Overall, there were no effects of TCPP exposure on the incidences of fetal head abnormalities (Appendix E^49^).

#### Skeletal

Skeletal malformations including discontinuous rib cartilage and full lumbar ribs were observed in TCPP-exposed animals. The incidences of these findings were low, however, and considered not exposure related (Table 14, Appendix E^49^). Associated skeletal variations observed in TCPP-treated groups included incomplete ossification of the sternebrae (II and V), floating extra rib, rudimentary ribs (lumbar I), and bipartite or dumbbell ossification of the thoracic centrum. A statistically significant increase (trend and pairwise comparison) was found for the percentage of fetuses with rudimentary ribs in all TCPP groups (22%, 23%, 22%) compared to the concurrent controls (14%). Although this finding appears to be exposure related, it is not dose dependent. This lack of dose response, a variation of limited biological significance, and lack of any other related effect suggests that the finding is not toxicologically relevant. Overall, examination of the fetal skeleton for osseous and cartilaginous defects of the skull (~50% of fetuses) and body only (100% of the fetuses) was not suggestive of an effect related to TCPP (Appendix E^49^).

Table 14 Summary of Selected Fetal Skeletal Findings in Rats in the Prenatal Developmental Toxicity Gavage Study of Tris(chloropropyl) Phosphate

| 0 mg/kg | 162.5 mg/kg | 325 mg/kg | 650 mg/kg
Total Number of Fetuses | 599 | 300 | 270 | 259
Number of Fetuses Examined | 599 | 300 | 270 | 259
Number of Litters Examined | 44 | 21 | 21 | 20
Thoracic Vertebrae – Thoracic Centrum
Fused – [M]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Bipartite ossification, bipartite cartilage – [M]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Unilateral ossification, bipartite cartilage – [M]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Unossified, bipartite cartilage – [M]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Bipartite ossification, normal cartilage – [V]
Fetuses | 2 (0.33) | 3 (1.00) | 1 (0.37) | 1 (0.39)
Litters | 2 (4.55) | 2 (9.52) | 1 (4.76) | 1 (5.00)
Bipartite ossification, dumbbell cartilage – [V]
Fetuses | 1 (0.17) | 0 (0.00) | 2 (0.74) | 1 (0.39)
Litters | 1 (2.27) | 0 (0.00) | 2 (9.52) | 1 (5.00)
Bipartite ossification, normal or dumbbell cartilage – [V]
Fetuses | 3 (0.50) | 3 (1.00) | 3 (1.11) | 2 (0.77)
Litters | 3 (6.82) | 2 (9.52) | 3 (14.29) | 1 (5.00)
Dumbbell ossification, normal cartilage – [V]
Fetuses | 7 (1.17) | 4 (1.33) | 4 (1.48) | 7 (2.70)
Litters | 6 (13.64) | 3 (14.29) | 4 (19.05) | 3 (15.00)
Dumbbell ossification, dumbbell cartilage – [V]
Fetuses | 3 (0.50) | 1 (0.33) | 2 (0.74) | 2 (0.77)
Litters | 2 (4.55) | 1 (4.76) | 2 (9.52) | 2 (10.00)
Dumbbell ossification, normal or dumbbell cartilage – [V]
Fetuses | 10 (1.67) | 5 (1.67) | 6 (2.22) | 9 (3.47)
Litters | 8 (18.18) | 4 (19.05) | 5 (23.81) | 4 (20.00)
Cartilage, normal ossification, dumbbell cartilage – [V]
Fetuses | 0 (0.00) | 1 (0.33) | 0 (0.00) | 0 (0.00)
Litters | 0 (0.00) | 1 (4.76) | 0 (0.00) | 0 (0.00)
Ribs
Cartilage, discontinuous – [M]
Fetuses | 0 (0.00) | 1 (0.33) | 0 (0.00) | 0 (0.00)
Litters | 0 (0.00) | 1 (4.76) | 0 (0.00) | 0 (0.00)
Cartilage, VIII attached to sternum – [M]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Discontinuous – [M]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Floating extra – [V]
Fetuses | 0 (0.00) | 0 (0.00) | 1 (0.37) | 0 (0.00)
Litters | 0 (0.00) | 0 (0.00) | 1 (4.76) | 0 (0.00)
Left, intercostal rib – [M]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Lumbar I full – [M]
Fetuses | 4 (0.67) | 4 (1.33) | 2 (0.74) | 3 (1.16)
Litters | 4 (9.09) | 3 (14.29) | 1 (4.76) | 2 (10.00)
Lumbar I rudimentary^a^ – [V]
Fetuses | 82 (13.69)**^#^ | 65 (21.67)** | 61 (22.59)**^#^ | 56 (21.62)**
Litters | 29 (65.91) | 17 (80.95) | 17 (80.95) | 15 (75.00)
Sternebrae
Sternebra II, incomplete ossification – [V]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Sternebra V, incomplete ossification —[V]
Fetuses | 2 (0.33) | 1 (0.33) | 4 (1.48) | 0 (0.00)
Litters | 2 (4.55) | 1 (4.76) | 3 (14.29) | 0 (0.00)
Sternebra(e), extra ossification site between sternebrae – [V]
Fetuses | 3 (0.50) | 1 (0.33) | 0 (0.00) | 0 (0.00)
Litters | 2 (4.55) | 1 (4.76) | 0 (0.00) | 0 (0.00)
Sternebra(e), Total, Incomplete Ossification – [V]
Fetuses | 3 (0.50) | 1 (0.33) | 4 (1.48) | 0 (0.00)
Litters | 3 (6.82) | 1 (4.76) | 3 (14.29) | 0 (0.00)
Sternebra(e), misaligned (>2, not V) – [V]
Fetuses | 1 (0.17) | 0 (0.00) | 0 (0.00) | 0 (0.00)
Litters | 1 (2.27) | 0 (0.00) | 0 (0.00) | 0 (0.00)

Upper row denotes number of affected fetuses and (%) and lower row the number of affected litters and (%).

Statistical analysis for litter data and for fetal data (without the litter effects) performed by the Cochran-Armitage (trend) and Fisher exact (pairwise) tests.

** Statistically significant (p ≤ 0.01) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column) in litter-based analysis of fetuses.

Statistical analysis of fetuses with litter-based adjustments performed by mixed-effects logistic regression.

^#^ Statistically significant (p ≤ 0.05) trend (denoted in vehicle control column) or pairwise comparison (denoted in dose group column) in litter-based analysis of fetuses.

[M] = malformation; [V] = variation.

^a^ Historical incidence for all routes: Fetuses 114/1,385 (8.23%), range 3.35–13.69%; Litters 53/97 (54.64%), range 26.32–65.91%.