# Materials and Methods

## Overview of Prenatal Developmental Toxicity Study Designs

Prenatal developmental toxicity studies are conducted to ascertain if in utero exposure to a test agent results in embryo-fetal death, structural malformations/variations, growth retardation, or functional deficits not secondary to overt maternal toxicity. Overt maternal toxicity has been shown to affect normal embryo-fetal growth and development (e.g., excessively lower maternal body weight gains and lower fetal weights, increased maternal stress in mice, and cleft palate).^21-23^ The presence of maternal toxicity, however, should not negate a priori an apparent fetal response. Rather, given the maternal/embryo-fetal interrelationship, maternal responses should be considered when interpreting fetal findings. Pregnant animals should be administered the highest feasible dose levels of test agent (or the limit dose) to achieve maximal dam and fetal exposure and sufficiently challenge the test system to identify potential developmental hazards.^24^

The conduct of a dose range-finding study helps determine dose selection when the potential for test agent-induced maternal toxicity is unknown and can provide preliminary information on embryo-fetal outcomes (e.g., postimplantation loss, changes in fetal weight, external defects) and informs the design for a prenatal developmental toxicity study. In the prenatal developmental toxicity study, fetal examination is expanded to include examination of the fetal viscera, head (soft tissue and skeletal components), and the skeleton for osseous and cartilaginous defects. Abnormalities are categorized in one of two groups: (1) malformations that are permanent structural changes that could adversely affect survival, development, or function; and (2) variations that are a divergence beyond the usual range of structural constitution but might not adversely affect survival or health,^22^ consistent with the descriptions by Makris et al.^25^ The study design for the dose range-finding and prenatal developmental toxicity studies is presented in Figure 1.

Figure 1

Design of a Dose Range-finding and Prenatal Developmental Toxicity Study in Rats

^a^Animals are exposed once daily from gestation day (GD) 6 to GD 20 and necropsied on GD 21.

^b^All fetuses are examined externally (including inspection of the oral cavity). Fetuses in the prenatal developmental toxicity study also are examined for visceral and skeletal effects with approximately 50% of the heads examined for soft tissue alterations.

## Procurement and Characterization

### Tris(chloropropyl) Phosphate

Tris(chloropropyl) phosphate (TCPP) was obtained from Albemarle Corporation (Orangeburg, SC) in two lots (101 and 134). Lot 101 was used in the dose range-finding study, and lots 101 and 134 were blended to form lot M072911NP, which was stored in two drums and used during the prenatal developmental toxicity study. Identity and purity of lots 101 and 134 were confirmed prior to blending (Table 2). Homogeneity of the blended lot M072911NP was confirmed both within the individual drums and between the two drums. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRI Global (Kansas City, MO) (Appendix A).

Table 2 Composition of Lots Used in the Prenatal Developmental Toxicity Studies of Tris(chloropropyl) Phosphate in Rats

Analysis | Lot 101^a^ | Lot 134 | Lot M072911NP^b^ Drum 1 | Lot M072911NP^b^ Drum 2
Elemental (%)
Carbon | 33.02 | ND | 33.06 | 32.93
Hydrogen | 5.64 | ND | 5.62 | 5.55
Nitrogen | 0.14 | ND | 0.09 | 0.10
Chlorine | 31.92 | ND | 32.00 | 32.19
Water: Karl Fischer (%) | 0.093 | ND | 0.038 | 0.039
Acid Number (mg KOH/g) | 0.011 | ND | 0.067 | ND
Ester Value (mg KOH/g) | 104.7 | ND | 105.85 | ND
Relative Density (g/mL) | 1.294 | ND | 1.296 | 1.296
Log P
TCPP Peak 1 | 2.69 | ND | 2.59 | ND
TCPP Peak 2 | 2.74 | ND | 2.65 | ND
Purity: GC/FID (%)^c^
System 1: DB-5
Sum of TCPP isomers | 96.04 | 98.79 | 97.04 | 97.43
Isomer 1 | 65.22 | 71.33 | 67.57 | 68.54
Isomer 2 | 26.80 | 24.29 | 25.65 | 25.21
Isomer 3 | 3.86 | 3.07 | 3.61 | 3.48
Isomer 4 | 0.16 | 0.14 | 0.21 | 0.20
Reportable impurities % (number)^d^ | 3.76 (7) | 1.14 (3) | 2.74 (8) | 2.35 (8)
System 2: DB-WAX
Sum of TCPP isomers | ND | ND | 97.50 | 97.91
Isomer 1 | ND | ND | 67.84 | 68.85
Isomer 2 | ND | ND | 25.87 | 25.42
Isomer 3 | ND | ND | 3.61 | 3.47
Isomer 4 | ND | ND | 0.18 | 0.17
Reportable impurities % (number)^d^ | ND | ND | 2.49 (6) | 2.09 (6)

ND = not determined; TCPP = tris(chloropropyl) phosphate; GC/FID = gas chromatography/flame ionization detection.

^a^ Used in the dose range-finding study.

^b^ Lots 101 and 134 were blended to generate lot M072911NP, used in the prenatal developmental toxicity study.

^c^ Isomers 1 through 4 were identified as tris(1-chloro-2-propyl) phosphate, bis(2-chloro-1-methylethyl) 2-chloropropyl phosphate, bis(2 chloropropyl) 2-chloroisopropyl phosphate, and tris(2-chloropropyl) phosphate, respectively (Appendix A).

^d^ Impurities ≥0.05% are listed.

Lots 101, 134, and M072911NP of the test chemical (clear oily liquids) were identified using proton and carbon-13 Fourier transform nuclear magnetic resonance (FT-NMR) spectroscopy. Because of the isomeric complexity of the test article, two-dimensional FT-NMR was performed on lot M072911NP including homonuclear correlation spectroscopy (COSY) and heteronuclear correlation (HETCOR) spectroscopy to confirm the data from the proton and carbon-13 NMR spectra. In addition, lots 101 and M072911NP were analyzed using Fourier transform infrared (FT-IR) and ultraviolet/visible (UV-Vis) spectroscopy and gas chromatography (GC) with mass spectrometry (MS) detection. GC/MS using electron ionization of lots 101 and M072911NP identified one major peak and three other peaks with similar molecular weights, indicating the presence of isomeric compounds (Table 2). The major peak (Isomer 1), identified as tris(1-chloro-2-propyl) phosphate, CASRN 13674-84-5, matched a literature spectrum.^26^ The three other isomers were identified as bis(2-chloro-1-methylethyl) 2-chloropropyl phosphate (Isomer 2, CASRN 76025-08-6); bis(2-chloropropyl) 2-chloroisopropyl phosphate (Isomer 3, CASRN 76649-15-5); and tris(2-chloropropyl) phosphate (Isomer 4, CASRN 6145-73-9).

The percentages of individual and combined isomers estimated for each lot using GC with flame ionization detection (FID) using two systems are shown in Table 2 and align with the range of percentages reported in commercial products (Table 1). For lots 101 and M072911NP, the following additional analyses were conducted: moisture content by Karl Fischer titration; elemental analyses for carbon, hydrogen, nitrogen, and chlorine (ICON Development Solutions (Whitesboro, NY); octanol:water partition coefficients (log P) of the major peak; density; and acid number and ester value. Acid number and ester value were determined using titration with standardized ~0.001 N sodium hydroxide and ~0.5 N hydrochloric acid, respectively, and are also shown for each isomer (Table 2). Results for elemental analyses for carbon, hydrogen, nitrogen, and chlorine for all lots were consistent with the theoretical values for TCPP. The purity of the lots, estimated based on the combined percentages of four isomers, was equal to or greater than 96% (Table 2).

To ensure stability, the test chemical was stored under inert gas at ~25°C, in sealed drums. Periodic analyses of lots 101 and M072911NP of the test chemical were performed prior to and during the animal studies by the analytical chemistry laboratory using FT-NMR and GC/FID; no degradation of the test chemical was detected.

### Methylcellulose

Methylcellulose was obtained from Spectrum Quality Products (Gardena, CA) in two lots (YX0540 and 2AJ0439). Lot YX0540 was used as the vehicle in the dose range-finding study and lot 2AJ0439 was used in the prenatal developmental toxicity study. The identity of both lots was confirmed by the analytical chemistry laboratory using FT-IR spectroscopy. Methoxy group content was determined by Galbraith Laboratories (Knoxville, TN) using titration with standardized sodium thiosulfate solution. Methoxy group content was 30.4% and 31.0% for lots YX0540 and 2AJ0439, respectively, both within the accepted range of 27.5–31.5%.

## Preparation and Analysis of Dose Formulations

Prior to conducting the dose range-finding study, formulation homogeneity studies at 1.56 mg/mL and 200 mg/mL and stability studies at 1.56 mg/mL were performed by the analytical chemistry laboratory using GC/FID. Homogeneity was confirmed, with the stipulation that high-dose formulations be stirred constantly during use to maintain homogeneity. Stability was confirmed for at least 7 days for dose formulations stored in sealed glass containers at ~5°C and for 3 hours under simulated animal room conditions at 5°C. The 1.56 mg/mL formulation was 93.8%, 88%, and 86.6% of the day 0 value at 7, 14, and 42 days, respectively, suggesting some loss over time. Additional stability studies were conducted at 32.5 and 130 mg/mL prior to the prenatal developmental toxicity study; stability of the 130 mg/mL formulation for up to 42 days was confirmed, whereas that of the 32.5 mg/mL formulation for up to 35 days was confirmed for formulations stored in sealed glass containers at ~5°C.

The dose formulations were prepared by the analytical chemistry laboratory once (dose range-finding study) or three times (prenatal developmental toxicity study) by mixing TCPP with a 0.5% methylcellulose solution to give the required concentrations with a dosing volume of 5 mL/kg. The dose formulations were stored at ~5°C in sealed glass jars for up to 30 days (dose range-finding study) or 15 days (prenatal developmental toxicity study).

Dose formulations of TCPP were analyzed by the analytical chemistry laboratory using GC/FID. During the dose range-finding study, the formulations were analyzed twice; all 10 dose formulations were within 10% of the target concentrations (Table A-3). Animal room samples received on day 36 were also analyzed; two of six were within 10% of the target concentrations and the other four were within 11–31%. During the prenatal developmental toxicity study, the dose formulations were prepared three times and analyzed once; all nine dose formulation samples were within 10% of the target concentrations (Table A-4). During the preparation of formulations, homogeneity was confirmed using the 32.5 and 130 mg/mL concentrations (Table A-4.). Animal room samples of each dose formulation were also analyzed; six were within 10% of the target concentrations and three were within 12–15%.

## Animal Source

Female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats for use in the dose range-finding and prenatal developmental toxicity studies were obtained from Envigo (formerly Harlan Laboratories, Inc., Dublin, VA or Indianapolis, IN) (Table 3). This stock is routinely used in NTP studies for toxicity evaluation. Sexually mature (12 to 13 weeks old) females were time-mated overnight at the vendor and were received on gestation day (GD) 2 for the dose range-finding study and on GD 1 or GD 2 for the prenatal developmental toxicity study. GD 0 was defined as the day positive evidence of mating was observed. In addition, 10 non-mated females were received for use as sentinels during the prenatal developmental toxicity study.

Table 3 Experimental Design and Materials and Methods in the Dose Range-finding and Prenatal Developmental Toxicity Gavage Studies of Tris(chloropropyl) Phosphate

Dose Range-finding Study | Prenatal Developmental Toxicity Study
Study Laboratory
RTI International (Research Triangle Park, NC) | RTI International (Research Triangle Park, NC)
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Dublin, VA) | Envigo (formerly Harlan Laboratories, Inc., Dublin, VA)
Day of Arrival
Gestation day (GD) 2 | GD 1 or GD 2
Average Age on Arrival
12 weeks | 12 to 13 weeks
Weight Range at Randomization
195.8 to 246.6 g on GD 3 | 203.5 to 256.0 g on GD 3
Calendar Day of First Dose (GD 6) and Last Dose (GD 20)
GD 6 (August 2, 2010) and GD 20 (August 16, 2010) | GD 6 (January 29, 2012) and GD 20 (February 15, 2012); staggered start
Duration of Dosing
GD 6 to GD 20, once daily | GD 6 to GD 20, once daily
Size of Study Groups
11 time-mated females | 50 time-mated females (2 vehicle control groups with 25 each), 25 time-mated females (treated groups)
Method of Randomization and Identification
Time-mated animals were uniquely identified on day of receipt by ear tag and assigned to dose group by body weight stratified randomization of GD 3 body weights using Instem Provantis^®^ (version 8) electronic data collection system. Each animal was assigned a unique animal number in Provantis. This number was linked to the respective marking and all data collected during the study were associated with the Provantis animal number. | Time-mated animals were uniquely identified on day of receipt by tail tattoo and assigned to dose group by body weight stratified randomization of GD 3 body weights using Instem Provantis (version 8) electronic data collection system. Each animal was assigned a unique animal number in Provantis. This number was linked to the respective marking and all data collected during the study were associated with the Provantis animal number.
Animals per Cage
1 | 1
Diet
Irradiated NIH-07 Certified Rodent Diet wafer diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum | Same as dose range-finding study
Water
Tap water (Durham, NC, municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as dose range-finding study
Cages
Solid-bottom polycarbonate cages (Ancare, Bellmore, NY), changed and rotated weekly | Solid-bottom polycarbonate cages (Lab Products, Inc., Seaford, DE), changed and rotated weekly
Bedding
Certified irradiated Sani-Chips^®^ hardwood cage bedding (P.J. Murphy Forest Products Corporation, Montville, NJ), changed weekly | Same as dose range-finding study
Cage Filters
Filter paper (Ancare, Bellmore, NY), changed weekly | Filter paper (Granville Milling Co., Creedmoor, NC), changed weekly
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks, rotated once during the study | Same as dose range-finding study
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as dose range-finding study
Doses
0, 300, 650, or 1,000 mg/kg in 0.5% methylcellulose (dosing volume 5 mL/kg) | 0, 162.5, 325, or 650 mg/kg in 0.5% methylcellulose (dosing volume 5 mL/kg)
Type and Frequency of Observation of Dams
Observed for viability twice daily from GD 3 through GD 20. Clinical observations were recorded twice daily from GD 3 until necropsy; (prior to dosing [out of cage] and at 1 to 3 hours post dose [cage side]) beginning on GD 6. Animals were weighed daily beginning on GD 3. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21. | Observed for viability twice daily from GD 3 through GD 20. Clinical observations were recorded once daily from GD 3 until necropsy; (prior to dosing [out of cage], and at 1 to 3 hours post dose [cage side]) from GD 6 through GD 20. Feed consumption was recorded at 3-day intervals from GD 3 through GD 21.
Primary Method of Euthanasia
100% CO_2_ (adults) or intraperitoneal injection of a solution containing sodium pentobarbital (fetuses) | 100% CO_2_ (adults) or oral administration of a solution containing sodium pentobarbital (fetuses)
Necropsy and Postmortem Evaluation of Females
On GD 21, terminal body and gravid uterine weights were recorded and the uterine contents examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live or dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained to visualize potential evidence of implantation sites. For animals removed early, gross necropsy including an examination of the thoracic and abdominal viscera was performed. The uterus of each female was examined to determine pregnancy status or, if no evidence of pregnancy, stained to visualize possible early implantation sites. | On GD 21, terminal body, adrenal glands, liver, ovary, and gravid uterine weights were recorded and the uterine contents examined. The number of corpora lutea on each ovary was recorded. The number and location of all fetuses (live or dead) and resorptions (early or late) and the total number of implantation sites were recorded; if no macroscopic evidence of pregnancy, the uterus was stained to visualize potential evidence of implantation sites. There were no early removals.
Fetal Evaluation
Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities that included inspection of the oral cavity for cleft palate. | Live fetuses were counted, sexed, weighed, and examined for external morphological abnormalities that included inspection of the oral cavity for cleft palate. Placental morphology was also evaluated. Live fetuses were euthanized and then examined for visceral morphological abnormalities by fresh dissection. The sex of each fetus was confirmed by internal examination. The heads from approximately half the fetuses in each litter were fixed, sectioned, and examined. All fetuses were eviscerated, fixed, stained, and examined for skeletal developmental variations, malformations, or other morphological findings.

GD = gestation day.

## Animal Health Surveillance

In accordance with the NTP Sentinel Animal Program (Appendix C), female sentinels were evaluated in the prenatal developmental toxicity study on January 31 and February 15, 2012. All test results were negative.

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the RTI International Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Experimental Design

In the dose range-finding and prenatal developmental toxicity studies, time-mated rats were housed individually, provided NIH-07 feed and water ad libitum, and observed at least twice daily for viability (morning and afternoon). Clinical observations were performed from GD 3 through GD 21 until removal, typically twice daily (at the time of dose administration and cage-side post dose). Females were weighed daily from GD 3 through GD 21. Feed consumption was recorded for GD 3 to 6, GD 6 to 9, GD 9 to 12, GD 12 to 15, GD 15 to 18, and GD 18 to 21. Details of the study design including animal source and identification, diet, water, husbandry, environmental conditions, euthanasia, necropsy, and fetal evaluations are summarized in Table 3. Information on feed composition and contaminants is provided in Appendix B.

On GD 21, rats were weighed, euthanized with CO_2_ inhalation, and examined for gross lesions of the thoracic and abdominal cavities. The gravid uterus, ovary, liver, and adrenal glands were excised and weighed (organs for prenatal developmental toxicology study only), and any placental findings were recorded. The numbers of implantation sites and corpora lutea visible on the surface of each ovary were recorded. Uterine contents were examined for pregnancy status and the number and location of all live and dead fetuses (a live fetus is defined as one that responds to stimuli; a dead fetus is defined as a term fetus that does not respond to stimuli and is not markedly autolyzed), and resorptions were recorded.

Resorptions were classified as early or late. Early resorptions included a conceptus characterized by a grossly necrotic mass that had no recognizable fetal form or presence of nidation sites (“pregnant by stain”). Late resorptions were characterized by grossly necrotic but recognizable fetal form with placental remnants visible.^27,28^ Postimplantation loss was calculated as the number of dead plus resorbed conceptuses divided by the total number of implantations (multiplied by 100). For each uterus with no macroscopic evidence of implantation, the uterus was stained with 10% (v/v) ammonium sulfide to visualize any possible early implantation sites.^29^

Adult females that were euthanized moribund, delivered early, or found dead received a gross necropsy that included an examination of the thoracic and abdominal viscera for evidence of dosing trauma or toxicity. The uterus of each female was examined and stained, if necessary, to determine pregnancy status. Females were not retained for further examination.

### Dose Range-finding Study

Time-mated rats were individually identified by ear tag and randomized by GD 3 body weight stratification into four groups using RTI International’s Instem™ Provantis^®^ (version 8.2.0) electronic data collection system.

Groups of 11 time-mated female rats were administered 0 (vehicle control), 300, 650, or 1,000 mg TCPP/kg body weight per day (mg/kg/day), based on the most recent weight, in 0.5% aqueous methylcellulose by gavage from GD 6 to GD 20. Vehicle control animals received aqueous methylcellulose alone; the dosing volume was 5 mL/kg. One thousand mg/kg was considered the limit dose for a prenatal development study in rats and was chosen as the high dose in the dose range-finding study. Dose selection was supported by developmental and two-generation reproduction studies reported in the literature.^3,5,16^

On GD 21, live fetuses of surviving females were counted, sexed, weighed, and examined for external morphological abnormalities, including inspection of the oral cavity for cleft palate. Fetuses were euthanized by intraperitoneal injection of a commercially available solution containing sodium pentobarbital. Fetuses were not retained following completion of the external examination.

### Prenatal Developmental Toxicity Study

On receipt (GD 1 or GD 2), time-mated rats were individually identified by tail tattoo and randomized, based on GD 3 body weight stratification, into five groups using RTI’s Instem™ Provantis^®^ (version 8.2.0) electronic data collection system. Dams were delivered 2 days apart to allow for a staggered study start.

Groups of 25 time-mated female rats were administered 0 (2 concurrent vehicle control groups), 162.5, 325, or 650 mg TCPP/kg body weight (based on the most recent weight) per day in 0.5% aqueous methylcellulose by gavage from GD 6 to GD 20 (15 days). The additional vehicle control group was included to generate additional control data for both maternal and fetal findings in this strain of rat. At the end of the study, the vehicle control groups were evaluated for reproducibility and combined for assessment of treatment-related effects because they were run concurrently. Vehicle control animals received aqueous methylcellulose alone; the dosing volume was 5 mL/kg.

On GD 21, fetuses were removed from the uterus, and live fetuses individually weighed. The uteri of animals that did not appear pregnant were examined for nidations (implantation sites) by staining with 0.5% ammonium sulfide.^29^ All fetuses were examined externally for alterations, including inspection of the oral cavity for cleft palate. Live fetuses were subsequently euthanized by intraperitoneal injection of sodium pentobarbital. Fetal sex was confirmed by inspection of gonads in situ. All fetuses were examined for soft tissue alterations under a stereomicroscope.^30,31^ The heads were removed from approximately half the fetuses in each litter and fixed in Bouin’s solution and subsequently examined by free-hand sectioning.^32^ This technique precludes skeletal evaluations of the skull; therefore, remaining heads and all fetuses were eviscerated, fixed in ethanol, macerated in potassium hydroxide, stained with alcian blue and alizarin red, and examined for subsequent cartilage and osseous alterations.^33,34^ External, visceral, and skeletal fetal alterations were recorded as developmental variations or malformations.

## Statistical Methods

In both the dose range-finding study and the main study, statistical analyses were performed on data from pregnant females that survived until the end of the study and were examined on GD 21 and from live fetuses. Statistical analyses were performed using SAS 9.3 (SAS Institute, Cary NC) software.

### Descriptive Statistics

Maternal Parameters: Maternal body weights were measured daily starting at GD 3 and reported as means. Terminal maternal body weights at GD 21 were adjusted for gravid uterine weight by subtracting the gravid uterine weight from the dam’s body weight. Body weight gains were calculated over each 3-day interval and from GD 6 to GD 21. Daily feed consumption was averaged over each 3-day interval and from GD 6 to GD 21. These continuous variables, in addition to gravid uterine weights, other organ weights, hematology, and clinical chemistry were summarized with means and standard errors.

Placental and Fetal Parameters: Data on uterine contents are reported as means and standard errors of counts per dam/litter (corpora lutea, implants, resorptions, dead fetuses) and as total numbers of occurrences (resorptions, dead fetuses). Data from females that were not pregnant or that did not survive to the end of the study were not included. Postimplantation loss is calculated as a percentage of the number of implants per dam. Fetal findings are reported as means and standard errors of counts per litter (numbers of live fetuses, male fetuses, female fetuses), means and standard errors of litter means (fetal weight, male fetal weight, female fetal weight), and total numbers of occurrences (total number of live fetuses). In addition, several calculated variables are reported, including the percentage of live male fetuses per litter.

Incidences of morphological findings from the gross, external, visceral, skeletal, and head examinations of pathology of placentae and fetuses are presented as number and percentage of affected fetuses and as number and percentage of affected litters.

### Analysis of Maternal Parameters and Uterine Contents

Maternal organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^35^ and Williams.^36,37^ Non-normally distributed variables, such as food consumption and uterine content endpoints, were analyzed using the nonparametric multiple comparison methods of Shirley^38^ (as modified by Williams^39^) and Dunn.^40^ For normally distributed and non-normally distributed variables, the Jonckheere test^41^ was used to assess the significance of dose-related trends at p < 0.01 to determine whether a trend-sensitive test (the Williams or Shirley test) was more appropriate than a test that does not assume a monotonic dose-related trend (the Dunnett or Dunn test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^42^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

Fetal body weights were analyzed using mixed-effects linear models, with litter as a random effect to account for potential within-litter correlations. To test for a linear trend, the numerical value of the dose was entered into the model and its significance was evaluated. For pairwise comparisons with the control group, a second mixed-effects model with dose entered into the model as a categorical variable was estimated, followed by the Dunnett^35^ and Hsu^43^ multiple comparison tests.

### Analysis of Incidences of Gross Pathology and Morphology Findings

Incidences of gross findings, malformations, and variations in the fetuses were summarized and analyzed as number of litters affected and as number of fetuses affected. Incidences of gross findings, malformations and numbers of litters affected were analyzed using the Cochran-Armitage trend test^44^ and the Fisher exact test.^45^ Incidences of numbers of fetuses affected were analyzed using mixed-effects logistic regression in which the litter was a random effect to account for potential litter effects.^46-48^ For each fetal finding, an initial mixed-effects logistic regression model used the numerical value of the dose to assess the significance of a dose-related trend; a subsequent logistic regression model incorporated dose as a categorical variable to compare each dose group with the control group. To conduct the mixed-effects logistic regression analyses, at least one finding was required per dose group and the correlation matrix describing the relationship between litters was required to be “positive definite.” If the mixed-effects logistic regression failed to converge or did not meet the specified criteria, two separate analyses were used to bracket the true p value. The Cochran-Armitage trend test and the Fisher exact test were used with the litter as the experimental unit to calculate the upper limit for the true p value and with the fetus as the experimental unit to calculate the lower limit for the true p value.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP developmental and reproductive toxicity studies. However, historical control data are often helpful in interpreting potential exposure-related effects, particularly for uncommon fetal findings that occur at a very low incidence. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors that might affect the background incidences of fetal findings at a variety of anatomical sites are diet, sex, strain/stock, route of exposure, study type, or laboratory that conducted the study. The NTP historical control database for teratology studies contains all fetal evaluations (e.g., teratology studies or modified one-generation studies) for each laboratory. In general, the historical control database for a given study includes studies using the same route of administration and study design. Historical control data for rats in this NTP Developmental and Reproductive Toxicity Technical Report, however, contain all studies conducted by the laboratory because of the limited number of studies available. The concurrent controls are included in the historical control data set. NTP historical controls are available online at https://ntp.niehs.nih.gov/go/historical_controls.

## Quality Assurance Methods

The dose range-finding and prenatal developmental toxicity studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations (21 CFR, Part 58). Records from these studies were submitted to the NTP Archives. The prenatal developmental toxicity study was audited retrospectively by an independent quality assessment contractor. Separate audits covered completeness and accuracy of the final study data tables for the dose range-finding and prenatal developmental toxicity studies and a draft of this NTP Developmental and Reproductive Toxicity Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this report.