# Introduction

## Tris(chloropropyl) Phosphate

Tris(chloropropyl) phosphate (TCPP) is a flame retardant commonly used in consumer products. Its chemical formula is C_9_H_18_Cl_3_O_4_P and its molecular weight is 327.57. The test article name represents the mixture. Its trade names are Amgard TMCP, Antiblaze 80, Antiblaze TMCP, and Fyrol PCF.

It was nominated to the National Toxicology Program (NTP) by the Consumer Product Safety Commission for toxicological testing. NTP is evaluating TCPP toxicity on various cellular or molecular targets in vitro (e.g., high throughput screening) and in vivo following subchronic and chronic exposure to rats and mice. Genotoxicity and immunotoxicity assessments also are under evaluation following TCPP exposure. Further information on NTP’s evaluation of the potential toxicity of TCPP is available at the Program’s website.^1^ The purpose of this report is to summarize and discuss TCPP effects on prenatal development in rats.

## Chemical and Physical Properties

TCPP is a clear colorless liquid mixture.^2-6^ TCPP has a molar mass of 327.59 g/mol and a relative density of 1.29 g/cm^3^ at 25°C. It has an estimated boiling point greater than 200°C, vapor pressure less than 2 mm Hg at 25°C, water solubility 1.6 g/L at 20°C, and log K_OW_ (octanol:water partition coefficient) 2.59.

## Production, Use, and Human Exposure

TCPP is produced as an isomeric mixture in a closed system by the reaction of phosphorus oxychloride and propylene oxide to generate a mixture of four isomers.^4^ The most abundant isomer in commercial products is tris(1-chloro-2-propyl) phosphate (50–85%) (Table 1). Additional isomers include bis(2-chloro-1-methylethyl)-2-chloropropyl phosphate (15–40%), bis(2-chloropropyl) 2-chloroisopropyl phosphate (<15%), and tris(2-chloropropyl) phosphate (<1%). Variations in manufacturing methods result in commercial formulations that contain different ratios of the four isomers. The TCPP mixture and commercial products are commonly referenced by the major isomer, tris(1-chloro-2-propyl) phosphate, and by CASRN 13674-84-5.^3^

Table 1 Tris(chloropropyl) Phosphate Isomers in Commercial Products^a^

Isomer | CASRN | Chemical Structure | Percentage (w/w) in Commercial Products
Tris(1-chloro-2-propyl) Phosphate 2-Propanol, 1-chloro-, 2,2ʹ,2ʺ-phosphate Tris(2-chloro-1-methylethyl) phosphate Tris(2-chloro isopropyl)phosphate | 13674-84-5 | | 50–85%
Bis(2-chloro-1-methylethyl) 2-Chloropropyl Phosphate Bis(1-chloro-2-propyl) 2-chloro-1-propyl phosphate Bis(2-chloro isopropyl) 2-chloropropyl phosphate | 76025-08-6 | | 15–40%
Bis(2-chloropropyl) 2-Chloroisopropyl Phosphate 2-Chloro-1-methylethyl bis(2-chloropropyl) phosphate Bis(2-chloropropyl) 2-chloro-1-methylethyl phosphate Bis(2-chloro-1-propyl) 1-chloro-2-propyl phosphate | 76649-15-5 | | <15%
Tris(2-chloropropyl) Phosphate 1-Propanol, 2-chloro-, phosphate (3:1) Tris(2-chloro-1-propyl) phosphate | 6145-73-9 | | <1%

TCPP isomers (in bold, noted by the U.S. Environmental Protection Agency [EPA] Registry Name) and common synonyms listed in the EPA Substance Registry Services database.^10^

^a^ Test article name represents the mixture.

The U.S. production volume of TCPP was approximately 54 million pounds in 2012.^7^ TCPP is used as a flame retardant within textiles, furniture (flexible polyurethane foam), and other related products. In addition, it is manufactured for use in construction materials (rigid polyurethane foam), electronic products, paints, coatings, and adhesives.^2^ TCPP has been proposed as a substitute for brominated flame retardants and as a replacement for other chlorinated flame retardants such as tris(2-chloroethyl) phosphate.^8,9^

Fate and transport of TCPP were recently summarized by the U.S. Environmental Protection Agency’s (EPA) Design for the Environment Branch.^3^ Available data suggest that TCPP is routinely found in drinking, ground, and surface waters. TCPP is expected to be highly mobile in soil because of its carbon-water partition values. It is also anticipated to be persistent in the environment based on the results of 28-day biodegradation studies, which suggest the half-life is greater than 60 days.^11^ TCPP has been detected in sediment, surface water, household dust, indoor air, and ambient air.^3^

Human exposure to TCPP can occur through inhalation, oral, or dermal contact. The EPA Office of Pollution Prevention and Toxics suggests that potential occupational exposure to TCPP is likely to occur through inhalation of vapors and dermal exposures during the manufacturing of consumer products containing TCPP^2^ or when working with consumer products containing TCPP. Because TCPP is considered ubiquitous in the environment, consumers could be exposed by inhalation of vapor, direct skin contact, and incidental ingestion. Exposures can occur in offices, homes, and other indoor environments as a result of using consumer products such as upholstered furniture containing TCPP. Children may be more susceptible to ingestion because of increased object-to-mouth behaviors.^9,12^

## Regulatory Status

TCPP is listed on the Toxic Substances Control Act (TSCA) Inventory. TCPP is one of several flame retardants included in that Inventory’s Work Plan, and EPA released a problem formulation and initial assessment document for the chlorinated phosphate ester cluster that includes TCPP in August 2015.^2^ The conclusion of that problem formulation is that EPA will assess risks to consumers, the general population, and aquatic organisms following exposure to TCPP and similar chemicals. Currently, no regulations restrict production or use of TCPP in the United States.

The European Union Risk Assessment Report for TCPP indicates no unacceptable risks for workers, consumers, or the general population, with the exception of effects on fertility and developmental toxicity related to dermal exposure to workers manufacturing TCPP.^5^ TCPP is currently not registered under the REACH (Registration, Evaluation, Authorisation, and Restriction of Chemicals) Regulation; therefore, the European Chemicals Agency (ECHA) has no usable data available for this substance from registered dossiers.^13^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

TCPP is readily absorbed and excreted in rats following gavage administration of 50 µmol [^14^C]TCPP/kg body weight.^14^ In this study, approximately 98% of the administered dose was recovered during 168 hours after dosing. Of the administered dose, 67%, 22%, and 7.7% were recovered in urine, feces, and expired air, respectively, within 48 hours. TCPP was rapidly distributed to tissues, with tissue-to-blood ratios highest in liver and kidney followed by lung, spleen, and adipose during the first 12 hours after administration. Elimination half-life in blood was estimated to be approximately 59 hours. Biliary excretion studies showed that approximately 45% of the administered dose was excreted in bile within 48 hours and that TCPP excreted in feces is likely from biliary excretion.

Additional absorption, disposition, metabolism, excretion, and toxicokinetic data are summarized in the European Union Risk Assessment Report^5^ and the EPA Design for the Environment Report, Flame Retardants Used in Flexible Polyurethane Foam: An Alternatives Assessment Update.^3^ These reports indicate that TCPP is readily absorbed and excreted, whose findings were based on animal studies.

### Humans

The literature contains no studies on the absorption, distribution, metabolism, or excretion of TCPP in humans. TCPP metabolism was investigated in vitro with human liver microsomes by Van den Eede et al.^15^ Incubation of microsomes with TCPP resulted in several Phase I metabolites including bis(1-chloro-2-propyl) phosphate, a major metabolite; bis(1-chloro-2-propyl) 1-hydroxy-2-propyl phosphate; bis(1-chloro-2-propyl) 1-carboxy-2-propyl phosphate; and 1-chloro-2-propyl,1-hydroxy-2-propyl phosphate. No Phase II metabolites were detected.

## Developmental and Reproductive Toxicity

### Experimental Animals

A prenatal developmental toxicity study conducted by Kawasaki et al.^16^ is reported in the literature.^16^ Wistar rats were fed a diet containing 0%, 0.01%, 0.1%, or 1% TCPP during gestation days (GD) 0 through GD 20 (n = 11 to 14). Daily TCPP intake for the exposed groups was estimated to be 6, 70, or 625 mg/kg body weight per day, respectively. Following exposure, no significant effects on dam survival, feed consumption, or body weight gain during gestation occurred. No effects on the number of implants, resorptions, or live or dead fetuses were found. An exam of fetal morphology demonstrated no significant external or visceral test article-related effects. Although no statistically significant increases in the incidences of skeletal abnormalities were found, dose-related increases in the incidences of cervical ribs and absent 13th ribs were reported, which suggest developmental toxicity.

Summaries of the results of a two-generation reproduction study in Wistar rats exposed to TCPP are presented in various hazard and risk assessment reports.^3,5^ Rats (28 per sex per group) received 0, 100, 333, or 1,000 mg TCPP/kg/day in the diet over two generations. Animals were fed TCPP 10 weeks prior to mating, during mating, and throughout gestation and lactation until study end. No treatment-related clinical observations or mortality in either parental generation were reported. TCPP exposure did not affect precoital time, mating index, fecundity index, fertility index, duration of gestation, or postimplantation loss. The mean number of pups delivered was lower in the F_0_ and F_1_ generations in the mid- and high-dose groups compared to the control.

### Humans

The literature contains no studies on the reproductive or developmental toxicity of TCPP in humans.

## General Toxicity

### Experimental Animals

The toxicity database, which includes published and unpublished data for TCPP, has been summarized in the National Industrial Chemicals Notification and Assessment Scheme,^17^ EPA’s Design for the Environment Branch,^3^ Environmental Health Criteria for Flame Retardants by the World Health Organization,^9^ SIDS (Screening Information Dataset) Initial Assessment Profile,^11^ European Union Risk Assessment Report,^5^ and the Agency for Toxic Substances and Disease Registry Toxicological Profile for Phosphate Ester Flame Retardants.^6^

Reported acute oral LD_50_ (lethal dose for 50% of exposed animals) values for TCPP range from 1,000 to 4,000 mg/kg body weight in male rats and 2,000 mg/kg in female rats.^4,5,11^ Common clinical observations observed in acute studies included ataxia, hunched posture, lethargy, labored respiration, increased salivation, body tremors, and piloerection. Macroscopic signs of toxicity included hemorrhagic lungs and dark liver and kidneys. The acute dermal LD_50_ in rats and rabbits is reported to be greater than 5,000 mg/kg and the inhalation LC_50_ (lethal concentration for 50% of exposed animals) in rats is greater than 4.6 mg/L.^4,5,11^ The EPA Design for the Environment Branch assigned a low hazard to TCPP for acute toxicity.^3^

In a 13-week toxicity study, Fyrol PCF^®^ (i.e., TCPP) administered in feed to Sprague Dawley rats (20 per sex per concentration) at exposure concentrations from 800 to 20,000 ppm had no effect on mortality, clinical observations, changes in hematology, clinical chemistry, or urinalysis parameters in the study animals.^18^ Body weights were decreased (<12% compared to controls) at the highest exposure concentration in males and females. Significantly increased liver weights were noted in all treated males and in the two highest exposure groups of females (7,500 and 20,000 ppm). Kidney weights were increased in males in the 7,500 and 20,000 ppm groups. Histopathological evaluation revealed minor changes in the liver, kidney, and thyroid gland, which were most prevalent in the two highest exposure concentration groups. The EPA Design for the Environment Branch assigned a moderate hazard to TCPP for repeat dose toxicity on the basis of these data.^3^

Subsequently, NTP conducted 13-week studies in rats and mice; the data are available in NTP’s Chemical Effects in Biological Systems database.^19^ TCPP was administered in feed at dietary concentrations of 0, 2,500, 5,000, 10,000, 20,000, or 40,000 ppm in rats and 0, 1,250, 2,500, 5,000, 10,000, or 20,000 ppm in mice (10 per sex per group). Rat exposures included a perinatal exposure from GD 6 to postnatal day 21 prior to the 13-week exposure. All rat dams exposed to 40,000 ppm (gestation) and all male pups (first week postweaning) in the 20,000 ppm group were removed because of overt toxicity. Body weights in all exposed rats at weaning were 13% to 30% lower than controls. In mice, no treatment-related mortality or clinical observations of toxicity were found. Terminal body weights were 12% (rats) and 29% (mice) lower than controls in the 20,000 ppm groups. Treatment-related increases occurred in relative liver (rats, mice) and thymus (rats) weights. In rats, treatment-related increases were found in the incidences of biliary hyperplasia and increased cellularity of the thymic cortex. In mice, the incidences of hepatocellular hypertrophy and male renal tubule epithelium cytoplasmic alterations were observed to be treatment related. In summary, subchronic exposure to TCPP in feed resulted in reduced dam and pup survival (rats); the liver, thymus, and kidney were considered primary targets of toxicity.

### Humans

No direct studies of tris(chloropropyl) phosphate exposure on human health have been conducted.

## Study Rationale

The Consumer Product Safety Commission nominated TCPP in 2005 because of its expected increased use as a flame retardant for flexible polyurethane foam used in home furnishings and construction materials.^20^ TCPP exposure to consumers via oral, dermal, and inhalation routes was also expected to increase, and the publicly available toxicity data at the time were considered limited. One report in the literature suggested that TCPP exposure might affect development^16^; therefore, NTP determined further studies were warranted to characterize the effects of oral TCPP administration in pregnant rats and on fetal development.