# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that could affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

Blood samples were collected and allowed to clot, and the serum was separated. All samples were processed appropriately and tested at the Research Animal Diagnostic Laboratory (RADIL), University of Missouri (Columbia, MO) for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the study are also listed.

Blood was collected from five female rats per time of collection for the prenatal developmental toxicity study.

Table C-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Multiplex Fluorescent Immunoassay
H-1 (Toolan’s H-1 virus) | Arrival, study termination
KRV (Kilham rat virus) | Arrival, study termination
Mycoplasma pulmonis | Arrival, study termination
PVM (pneumonia virus of mice) | Arrival, study termination
RCV/SDA (rat coronavirus/sialodacryoadenitis virus) | Arrival, study termination
RMV (rat minute virus) | Arrival, study termination
RPV (rat parvovirus) | Arrival, study termination
RTV (rat theilovirus) | Arrival, study termination
Sendai | Arrival, study termination
TMEV (Theiler’s murine encephalomyelitis virus) | Arrival, study termination

## C.2 Results

All test results were negative.