# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NIH-07 Rat and Mouse Ration

Table B-1 Ingredients of NIH-07 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground #2 Yellow Shelled Corn | 24.50
Ground Hard Winter Wheat | 23.00
Soybean Meal (49% Protein) | 12.0
Fish Meal (60% Protein) | 10.0
Wheat Middlings | 10.0
Alfalfa Meal (Dehydrated, 17% Protein) | 4.0
Soy Oil (Without Preservatives) | 2.5
Dried Brewer’s Yeast | 2.0
Calcium Phosphate, Dibasic (USP) | 1.3
Calcium Carbonate (USP) | 0.5
Sodium Chloride | 0.5
Premixes (Vitamin and Mineral) | 0.25
Choline Chloride (70% Choline) | 0.09

USP = United States Pharmacopeia.

Table B-2 Vitamins and Minerals in NIH-07 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 6,062 IU | Stabilized vitamin A palmitate or acetate
D | 5,070 IU | D-activated animal sterol
K | 3.09 mg | Menadione sodium bisulfite complex
E | 22 IU | α-Tocopheryl acetate
Niacin | 33 mg | –
Folic Acid | 2.4 mg | –
D-Pantothenic Acid | 19.8 mg | d-Calcium pantothenate
Riboflavin | 3.8 mg | –
Thiamin | 11 mg | Thiamine mononitrate
B_12_ | 50 µg | –
Pyridoxine | 6.5 mg | Pyridozine hydrochloride
Biotin | 0.15 mg | d-Biotin
Minerals
Iron | 132 mg | Iron sulfate
Zinc | 18 mg | Zinc oxide
Manganese | 66 mg | Manganese oxide
Copper | 4.4 mg | Copper sulfate
Iodine | 1.5 mg | Calcium iodate
Cobalt | 0.44 mg | Cobalt carbonate

IU = international unit.

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NIH-07 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 24.7 | 24.7 | 1
Crude Fat (% by Weight) | 5.6 | 5.6 | 1
Crude Fiber (% by Weight) | 3.42 | 3.42 | 1
Ash (% by Weight) | 7.17 | 7.17 | 1
Amino Acids (% of Total Diet)
Arginine | 1.374 ± 0.049 | 1.31–1.43 | 5
Cysteine | 0.325 ± 0.029 | 0.29–0.372 | 5
Glycine | 1.120 ± 0.041 | 1.06–1.16 | 5
Histidine | 0.504 ± 0.008 | 0.49–0.51 | 5
Isoleucine | 0.973 ± 0.018 | 0.95–0.99 | 5
Leucine | 1.982 ± 0.036 | 1.93–2.02 | 5
Lysine | 1.250 ± 0.039 | 1.22–1.32 | 5
Methionine | 0.485 ± 0.011 | 0.46–0.49 | 5
Phenylalanine | 1.086 ± 0.017 | 1.07–1.11 | 5
Threonine | 0.907 ± 0.024 | 0.88–0.94 | 5
Tryptophan | 0.274 ± 0.014 | 0.26–0.29 | 5
Tyrosine | 0.871 ± 0.017 | 0.85–0.89 | 5
Valine | 1.120 ± 0.022 | 1.11–1.16 | 5
Essential Fatty Acids (% of Total Diet)
Linoleic | 2.23 ± 0.223 | 2.04–2.59 | 5
Linolenic | 0.24 ± 0.0249 | 0.22–0.28 | 5
Vitamins
Vitamin A (IU/kg) | 5,350 | 5,350 | 1
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 73.72 ± 4.40 | 69.5–78.7 | 5
Thiamine (ppm)^b^ | 16 | 16 | 1
Riboflavin (ppm) | 14.42 ± 3.64 | 10–19.8 | 5
Niacin (ppm) | 95.96 ± 7.28 | 87–106 | 5
Pantothenic Acid (ppm) | 45.26 ± 1.487 | 43.2–47.4 | 5
Pyridoxine (ppm)^b^ | 11.96 ± 1.948 | 9.63–14.9 | 5
Folic Acid (ppm) | 2.39 ± 0.439 | 1.69–2.74 | 5
Biotin (ppm) | 0.3 ± 0.0463 | 0.25–0.37 | 5
Vitamin B_12_ (ppb) | 49.28 ± 8.364 | 41.8–61.6 | 5
Minerals
Calcium (%) | 1.260 | 1.260 | 1
Phosphorus (%) | 0.967 | 0.967 | 1
Potassium (%) | 0.814 ± 0.035 | 0.769–0.865 | 5
Chloride (%) | 0.572 ± 0.076 | 0.441–0.628 | 5
Sodium (%) | 0.344 ± 0.018 | 0.318–0.365 | 5
Magnesium (%) | 0.182 ± 0.006 | 0.174–0.192 | 5
Iron (ppm) | 394.8 ± 38.848 | 348–455 | 5
Manganese (ppm) | 86.2 ± 4.77 | 80.7–93.2 | 5
Zinc (ppm) | 64.66 ± 14.521 | 52.4–89.2 | 5
Copper (ppm) | 13.12 ± 0.949 | 11.9–14.1 | 5
Iodine (ppm) | 1.876 ± 0.986 | 0.8–3.45 | 5
Chromium (ppm) | 1.304 ± 0.225 | 0.97–1.59 | 5
Cobalt (ppm) | 0.532 ± 0.179 | 0.25–0.73 | 5

IU = international unit.

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine).

Table B-4 Contaminant Levels in NIH-07 Rat and Mouse Ration^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.587 | 0.587 | 1
Cadmium (ppm) | 0.096 | 0.096 | 1
Lead (ppm) | 0.106 | 0.106 | 1
Mercury (ppm) | 0.016 | 0.016 | 1
Selenium (ppm) | 0.488 | 0.488 | 1
Aflatoxins (ppb) | <5.00 | – | 1
Nitrate Nitrogen (ppm)^c^ | <10.0 | – | 1
Nitrite Nitrogen (ppm)^c^ | <0.61 | – | 1
BHA (ppm)^d^ | <1.0 | – | 1
BHT (ppm)^d^ | <1.0 | – | 1
Aerobic Plate Count (CFU/gm) | <10 | – | 1
Coliform (MPN/gm) | <3 | – | 1
Escherichia coli (MPN/gm) | <10 | – | 1
Salmonella (MPN/gm) | Negative | – | 1
Total Nitrosamines (ppb)^e^ | 8.2 | 8.2 | 1
N-Nitrosodimethylamine (ppb)^e^ | 1.1 | 1.1 | 1
N-Nitrosopyrrolidine (ppb)^e^ | 7.1 | 7.1 | 1
Pesticides (ppm)
α-BHC | <0.01 | – | 1
β-BHC | <0.02 | – | 1
γ-BHC | <0.01 | – | 1
δ-BHC | <0.01 | – | 1
Heptachlor | <0.01 | – | 1
Aldrin | <0.01 | – | 1
Heptachlor Epoxide | <0.01 | – | 1
DDE | <0.01 | – | 1
DDD | <0.01 | – | 1
DDT | <0.01 | – | 1
HCB | <0.01 | – | 1
Mirex | <0.01 | – | 1
Methoxychlor | <0.05 | – | 1
Dieldrin | <0.01 | – | 1
Endrin | <0.01 | – | 1
Telodrin | <0.01 | – | 1
Chlordane | <0.05 | – | 1
Toxaphene | <0.10 | – | 1
Estimated PCBs | <0.20 | – | 1
Ronnel | <0.01 | – | 1
Ethion | <0.02 | – | 1
Trithion | <0.05 | – | 1
Diazinon | <0.10 | – | 1
Methyl Chlorpyrifos | 0.0706 | 0.0706 | 1
Methyl Parathion | <0.02 | – | 1
Ethyl Parathion | <0.02 | – | 1
Malathion | 0.0295 | 0.0295 | 1
Endosulfan I | <0.01 | – | 1
Endosulfan II | <0.01 | – | 1
Endosulfane Sulfate | <0.03 | – | 1

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl; PCB = polychlorinated biphenyl.

^a^ All samples were irradiated.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.