# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization

### A.1.1 Tris(chloropropyl) Phosphate (TCPP)

TCPP was obtained from Albemarle Corporation (Orangeburg, SC) in two lots (101 and 134). Lot 101 was used in the dose range-finding study, and lots 101 and 134 were blended to form lot M072911NP, which was divided into two drums and used during the prenatal developmental toxicity study. Homogeneity of the blended lot M072911NP was confirmed both within the individual drums and between the two drums. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRI Global (Kansas City, MO) for the study laboratory at RTI International (Research Triangle Park, NC). Reports on analyses performed in support of the TCPP studies are on file at the National Institute of Environmental Health Sciences.

Lots 101, 134, and M072911NP of the test chemical (clear oily liquids) were identified as TCPP using proton and carbon-13 Fourier transform nuclear magnetic resonance (FT-NMR) spectroscopy. In addition, lots 101 and M072911NP were identified as TCPP using Fourier transform infrared (FT-IR) and ultraviolet/visible (UV-Vis) spectroscopy, gas chromatography (GC) with mass spectrometry (MS) detection, and measurement of density. FT-NMR, FT-IR, and UV-Vis spectra were consistent with the structure of TCPP. Because of the isomeric complexity of the test article, two-dimensional FT-NMR was performed on lot M072911NP including homonuclear correlation spectroscopy (COSY) and heteronuclear correlation (HETCOR) spectroscopy to confirm the data from the proton and carbon-13 NMR spectra. Representative FT-IR and proton NMR spectra are presented in Figure A-1 and Figure A-2, respectively. GC/MS electron ionization analyses of lots 101 and M072911NP identified one major peak and three isomers with molecular weights of 327.6. The primary isomer (Isomer 1; tris(1-chloro-2-propyl) phosphate, CASRN No. 13674-84-5) matched a literature spectrum^26^; the three other isomers were identified as bis (1-chloro-2-propyl) 2-chloro-1-propyl phosphate (Isomer 2, CASRN No. 76025-08-6); bis (2-chloro-1-propyl) 1-chloro-2-propyl phosphate (Isomer 3, CASRN No. 76649-15-5); and tris(2-chloro-1-propyl) phosphate (Isomer 4, CASRN No. 6145-73-9) (Table 2). The densities (at 21°C) of lots 101 and M072911NP were determined to be 1.2936 and 1.2958–1.2959, respectively.

The moisture content of lots 101 and M072911NP was determined by Karl Fischer titration. Elemental analyses for carbon, hydrogen, nitrogen, and chlorine were conducted by ICON Development Solutions (Whitesboro, NY) on lots 101 and M072911NP. The purity profiles of lots 101, 134, and M072911NP were determined using GC with flame ionization detection (FID), and octanol:water partition coefficients were determined for the two largest peaks of the profiles for lots 101 and M072911NP. Acid number and ester value were determined for lots 101 and M072911NP using titration with standardized ~0.001 N sodium hydroxide and ~0.5 N hydrochloric acid, respectively.

For lot 101, Karl Fischer titration indicated a water content of 0.093–0.100%. Elemental analyses for carbon, hydrogen, nitrogen, and chlorine were consistent with the theoretical values for TCPP. GC/FID analysis by system A (Table A-1) detected four TCPP peaks with a combined area of 96.04% of the total peak area and seven reportable impurities with individual areas ≥0.05% of the total peak area. The largest peak in this analysis comprised 65.22% of the total peak area, and log P values for the two largest peaks in this profile were determined to be 2.69 and 2.74, respectively. The average acid number for lot 101 was determined to be 0.011 mg potassium hydroxide (KOH)/g, and the average ester value was calculated to be 104.7 mg KOH/g. The overall purity of lot 101 was determined to be approximately 96%.

For lot 134, the GC/FID purity profile by system A detected four TCPP peaks with a combined relative area of 98.79% and three reportable impurities ≥0.05% of the total peak area; the largest peak comprised 71.33% of the total peak area. Coupled with the proton and carbon-13 FT-NMR identity confirmation for lot 134, these results indicated that lot 134 was suitable for blending with lot 101 to constitute lot M072911NP.

Lot M072911NP was determined to contain 0.038–0.039% water by Karl Fischer titration. Elemental analyses for carbon, hydrogen, nitrogen, and chlorine were consistent with the theoretical values for TCPP. GC/FID by system A detected four TCPP peaks accounting for 97.04–97.43% of the total peak area and eight minor peaks with individual areas ≥0.05% of the total peak area. The major peak in this analysis comprised 67.57–68.54% of the total peak area and log P values for the two largest peaks in this profile were determined to be 2.59 and 2.65, respectively. Using a more polar column, GC/FID by system B detected four TCPP peaks with a combined area of 97.50–97.91% of the total peak area and six reportable impurities with individual areas ≥0.05% of the total peak area. The major peak in this analysis comprised 67.84–68.85% of the total peak area. The average acid number for lot M072911NP was determined to be 0.067 mg KOH/g and the average ester value was calculated to be 105.85 mg KOH/g. The overall purity of lot M072911NP was determined to be 97% or greater. A summary of these analyses is given in Table 2.

Accelerated stability studies of lot 101 of the test chemical were conducted by the analytical chemistry laboratory using GC/FID by system A. Stability of the bulk chemical was confirmed for at least 2 weeks when stored in glass vials sealed with Teflon^®^-lined crimp caps at temperatures up to 60°C. To ensure stability, the test chemical was stored under inert gas at ~25°C, in sealed drums. Periodic analyses of lots 101 and M072911NP of the test chemical were performed prior to and during the animal studies by the analytical chemistry laboratory using FT-NMR and GC/FID; no degradation of the test chemical was detected.

### A.1.2 Methylcellulose

Methylcellulose was obtained from Spectrum Quality Products (Gardena, CA) in two lots (YX0540 and 2AJ0439). Lot YX0540 was used as the vehicle in the dose range-finding study and lot 2AJ0439 was used in the prenatal developmental toxicity study. The identity of both lots was confirmed by the analytical chemistry laboratory using FT-IR spectroscopy; all spectra were consistent with the structure of methylcellulose and the literature.^66^ Methoxy group content, determined by Galbraith Laboratories (Knoxville, TN) using titration with standardized sodium thiosulfate solution, was 30.4% and 31.0% for lots YX0540 and 2AJ0439, respectively, both within the accepted range of 27.5–31.5%.

## A.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared once (dose range-finding study) or three times (prenatal developmental toxicity study) by mixing TCPP with a 0.5% methylcellulose solution to give the required concentrations (Table A-2). The dose formulations were stored at ~5°C in sealed glass jars for up to 30 days (dose range-finding study) or 15 days (prenatal developmental toxicity study).

Prior to conducting the dose range-finding study, homogeneity studies of 1.56 mg/mL and 200 mg/mL formulations and stability studies of the 1.56 mg/mL formulation were performed by the analytical chemistry laboratory using GC/FID by system A (Table A-1). Homogeneity was confirmed, with the stipulation that high-dose formulations be stirred constantly during use to maintain homogeneity. Stability was confirmed for at least 7 days for dose formulations stored in sealed glass containers at ~5°C and for 3 hours under simulated animal room conditions; at ~5°C, the 1.56 mg/mL formulation was 93.8%, 88%, and 86.6% of the day 0 value at 7, 14, and 42 days, respectively, suggesting some loss over time. Additional stability studies were conducted at 32.5 and 130 mg/mL prior to the prenatal developmental toxicity study; stability of the 130 mg/mL formulation for up to 42 days was confirmed, while that of the 32.5 mg/mL formulation was confirmed for up to 35 days for formulations stored in sealed glass containers at ~5°C.

Periodic analyses of the dose formulations of TCPP were conducted by the analytical chemistry laboratory using GC/FID by system A. During the dose range-finding study, the dose formulations were analyzed one day after preparation and after storage at ~5°C for 7 days; all 10 dose formulation samples were within 10% of the target concentrations (Table A-3). Animal room samples received on day 36 were also analyzed; two of six were within 10% of the target concentrations. During the prenatal developmental toxicity study, the dose formulations were prepared three times, and all nine dose formulation samples were within 10% of the target concentrations (Table A-4). Animal room samples of these dose formulations were also analyzed; six of nine were within 10% of the target concentrations.

Table A-1 Gas Chromatography Systems Used in the Gavage Studies of Tris(chloropropyl) Phosphate^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame Ionization | DB-5, 30 m × 0.53 mm, 1.5 µm film (J&W Scientific, Folsom, CA) | Helium at ~10 mL/minute | 160°C for 5 minutes, then 1°C/minute to 180°C, held for 5, 10, 15, or 25 minutes
System B
Flame Ionization | DB™-WAX, 30 m × 0.53 mm, 1.0 µm film (J&W Scientific) | Helium at ~10 mL/minute | 200°C for 5 minutes, then 1°C/minute to 230°C, held for 15 minutes

^a^ The gas chromatographs were manufactured by Agilent Technologies, Inc. (Santa Clara, CA).

Table A-2 Preparation and Storage of Dose Formulations in the Gavage Studies of Tris(chloropropyl) Phosphate

Dose Range-finding Study | Prenatal Developmental Toxicity Study
Preparation
The dosing vehicle was prepared by mixing methylcellulose with heated, deionized water while stirring and then diluting with water to form a 0.5% solution, which was allowed to cool. For the dose formulations, the appropriate amount of TCPP was weighed and transferred into a 2-L beaker, diluted with the vehicle, mixed using a POLYTRON^®^ PT-10-35 homogenizer with a PTA 10TS low-foaming generator for approximately 2 minutes, and then stirred using a stir bar for approximately 5 minutes. The doses were prepared once. | Same as the 3-week dose range-finding study except that the doses were prepared three times.
Chemical Lot Number
101 | M072911NP
Maximum Storage Time
30 days | 15 days
Storage Conditions
Stored in glass jars with lids at ~5°C | Stored in wide-mouth clear glass jars with lids at ~5°C
Study Laboratory
RTI International (Research Triangle Park, NC) | RTI International (Research Triangle Park, NC)

Table A-3 Results of Analyses of Dose Formulations Administered to Female Rats in the Dose Range-finding Gavage Study of Tris(chloropropyl) Phosphate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
July 19, 2010 | July 20, 2010^b^ | 60 | 60.2 | 0
| | 60 | 60.2 | 0
| | 60 | 60.4 | +1
| | 130 | 130.3 | 0
| | 200 | 207.3 | +4
| | 200 | 206.5 | +3
| | 200 | 204.5 | +2
| July 27, 2010 | 60 | 59.8 | 0
| | 130 | 129.7 | 0
| | 200 | 205.3 | +3
| August 24, 2010^c^ | 60 | 75.0^d^ | +25
| | 60 | 78.5^d^ | +31
| | 130 | 156.3^d^ | +20
| | 130 | 143.9^d^ | +11
| | 200 | 209.4 | +5
| | 200 | 202.6 | +1

^a^ Results of triplicate analyses. Dosing volume = 5 mL/kg; 60 mg/mL = 300 mg/kg, 130 mg/mL = 650 mg/kg, 200 mg/mL = 1,000 mg/kg.

^b^ For the 60 and 200 mg/mL dose formulations, the triplicate results are for homogeneity analyses from samples collected from the top, middle, and bottom of each vessel.

^c^ Animal room samples.

^d^ Formulation was outside the acceptable range of ±10% of target concentration but determined to not affect the quality or integrity of the study.

Table A-4 Results of Analyses of Dose Formulations Administered to Female Rats in the Prenatal Developmental Toxicity Gavage Study of Tris(chloropropyl) Phosphate

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
January 20, 2012 | January 20, 2012 | 32.5 | 32.8 | +1
| | 65 | 64.7 | 0
| | 130 | 130.9 | +1
| February 9, 2012^b^ | 32.5 | 30.5 | −6
| | 65 | 55.2 | −15
| | 130 | 123.2 | −5
February 2, 2012 | February 2, 2012 | 32.5 | 32.2. | −1
| | 65 | 64.2 | −1
| | 130 | 130.3 | 0
| February 16, 2012^b^ | 32.5 | 28.7 | −12
| | 65 | 57.4 | −12
| | 130 | 126.7 | –3
February 8, 2012 | February 8, 2012 | 32.5 | 32.9 | +1
| | 65 | 62.5 | −4
| | 130 | 125.8 | −3
| February 21, 2012^b^ | 32.5 | 31.0 | −5
| | 65 | 61.1 | −6
| | 130 | 126.9 | −2

^a^ Results of triplicate analyses. Dosing volume = 5 mL/kg; 32.5 mg/mL = 162.5 mg/kg, 65 mg/mL = 325 mg/kg, 130 mg/mL = 650 mg/kg.

^b^ Animal room samples.

Figure A-1

Fourier Transform Infrared Absorption Spectrum of Tris(chloropropyl) Phosphate

Figure A-2

Proton Nuclear Magnetic Resonance Spectrum of Tris(chloropropyl) Phosphate