# Peer Review

The Draft Report on Carcinogens Monograph on Helicobacter pylori (chronic infection) was peer reviewed by letter by individuals with expertise in H. pylori and cancer. The reviewers served as independent scientists and not as representatives of any institution, company, or governmental agency.

The peer reviewers were charged to:

1. Comment on whether the draft monograph was technically correct, clearly stated, and objectively presented.
2. Provide opinion on whether there is currently or was in the past significant human exposure to H. pylori.

Each peer reviewer independently was asked to provide opinion on:

1. Whether the scientific evidence supported the NTP’s preliminary conclusion on the level of evidence for carcinogenicity from cancer studies in humans.
2. Whether the scientific evidence supported the NTP’s preliminary policy decision on H. pylori for listing in the Report on Carcinogens.

The monograph was revised based on NTP’s consideration of the peer-review comments.

## Peer Reviewers

- Rolando Herrero, M.D., Ph.D.
  Head
  Prevention and Implementation Group
  Early Detection and Prevention Section
  International Agency for Research on Cancer
  Lyon, France
- Julie Parsonnet, M.D.
  George DeForest Barnett Professor in Medicine
  Professor of Medicine
  Professor of Health Research and Policy
  Division of Infectious Diseases and Geographic Medicine
  Division of Epidemiology
  Stanford University Medical Center
  Stanford, California, USA
- Traci L. Testerman, Ph.D.
  Assistant Professor
  Department of Pathology, Microbiology, and Immunology
  University of South Carolina School of Medicine
  Columbia, South Carolina, USA