# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Executed and coordinated project activities, including conception, design, planning, conduct, or technical review of cancer hazard evaluation
  Ruth M. Lunn, Dr.P.H., Project Co-lead
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Executed and coordinated project activities, including conception, design, planning, conduct, or technical review of cancer hazard evaluation
  Whitney Arroyave, Ph.D., Project Co-lead