# Glossary

Animal reservoir: An animal in which an infectious agent (e.g., H. pylori) lives and multiplies in such a manner that it can be transmitted to a susceptible host.
Antrum: The lower part of the stomach, sometimes called the pyloric antrum.
ASEAN countries: Association of Southeast Asian Nations. The 10 members are Brunei Darussalam, Cambodia, Indonesia, Laos, Malaysia, Myanmar, Philippines, Singapore, Thailand, and Vietnam.
Atrophic gastritis: The end stage of chronic gastritis, in which gastric glandular cells are lost and replace by intestinal and fibrous tissues.
Barrett’s esophagus: A complication of gastroesophageal reflux disease (GERD) in which the normal tissue lining the esophagus is altered to resemble the tissue that lines the intestine.
Birth cohort effect: Variations in a characteristic, such as H. pylori infection, among individuals that share a common year or range of years of birth.
Bismuth quadruple therapy: A combination of a bismuth salt, a proton pump inhibitor (PPI), and two antibiotics used to treat H. pylori infections.
Cardia: The opening that connects the esophagus and the upper part of the stomach or that part of the stomach connected to the esophagus.
Cardia gastric cancer: Cancer of the lining of the stomach found in the top part of the organ (i.e., the cardia).
Chemotaxis: Movement of an organism, for example an H. pylori bacterium, in response to a chemical stimulus, including acidity.
Clarithromycin triple therapy: A combination of clarithromycin (an antibiotic), amoxicillin (an antibiotic), and omeprazole (a proton pump inhibitor) used to treat H. pylori infections.
Corpus: The body of the stomach, which is the largest of the four parts that make up the stomach.
COX-2 inhibitor: A nonsteroidal anti-inflammatory drug (NSAID) that directly targets cyclooxygenase-2 (COX-2) enzyme.
Enzyme-linked immunosorbent assay (ELISA): An immunological assay commonly used to measure antibodies in biological samples.
Enterohepatic tissues: The intestinal tract, biliary tree, and liver.
EPIYA motif: A polymorphic pattern of Glu-Pro-Ile-Tyr-Ala amino acid repeats that contains the main sites for phosphorylation of CagA.
Flagella (singular flagellum): A whip-like structure that allows a cell to move.
Gastritis: Inflammation, irritation, or erosion of the lining of the stomach.
Gram-negative bacteria: Bacteria that are not stained by the crystal violet dye used in the Gram stain protocol and thus appear red or pink due to the counterstain (usually safranin).
Helical: A geometric shape that curves continuously around a center point; for example, a line wrapped around a cylinder or a cone.
Immunoblot: A laboratory test that looks for antibodies the body makes against different molecules, or “antigens,” that are part of a bacteria, e.g., H. pylori.
INS-GAS transgenic mice: Mice that have been genetically modified to produce more gastrin (a peptide that increases the secretion of gastric acid.
Intervention studies: A test of preventive or therapeutic measure(s) in which study subjects are followed prospectively with one group of subjects receiving the treatment and the other serving as the control; the control group can receive no treatment, a placebo, or a standard treatment for comparison.
Life-years saved: A measure of the additional number of years that a person lives as a result of receiving a treatment.
Mucosal: Related to the mucosa, which is the thin skin that covers the inside surface of body parts such as the nose and mouth and produces mucus to protect them.
Non-cardia gastric cancer: Cancer of the lining of the stomach found in any part of the organ other than the top part (i.e., the cardia).
Peptic ulcers: Open sores that develop on the inside lining of the stomach and the upper portion of the small intestine.
Prevalence: The number of cases of a disease that are present in a particular population at a given time.
Sensitivity: The ability of a clinical test to correctly identify those patients with the disease.
Serology tests: Blood tests that look for antibodies, e.g., to H. pylori.
Specificity: The ability of a clinical test to correctly identify those patients without the disease.
Spiral: A shape consisting of curves, with each one above or wider than the one before.
Tissue biopsy: A sample of tissue removed from the body for closer examination, usually for diagnostic purposes.
Urease: An enzyme that converts urea to ammonia and carbon dioxide.