# Abbreviations

  ASEAN: Association of Southeast Asian Nations
  BabA: blood group antigen binding adhesin A
  CAG: chronic atrophic gastritis
  CagA: cytotoxin-associated gene A
  CI: confidence interval
  COX 2: cyclooxygenase 2
  CPS II: Cancer Prevention Study II
  DNA: deoxyribonucleic acid
  DYS: dysplasia
  ELISA: enzyme-linked immunosorbent assay
  FDA: U.S. Food and Drug Administration
  FDASIA: Food and Drug Administration Safety and Innovation Act
  GAIN: Generating Antibiotic Incentives Now
  GERD: gastro-esophageal reflux disease
  HAWC: Health Assessment Workspace Collaborative
  HDI: human development index
  HR: hazard ratio
  IgA: immunoglobulin A
  IgG: immunoglobulin G
  IM: intestinal metaplasia
  IQR: interquartile range
  MALT: mucosa-associated lymphoid tissue
  MNU: N-methyl-N-nitrosourea
  NHANES: National Health and Nutrition Examination Survey (United States)
  OR: odds ratio
  ORoC: Office of the Report on Carcinogens
  PPI: proton pump inhibitor
  RoC: Report on Carcinogens
  RR: relative risk
  TGF-B: transforming growth factor beta
  VacA: vacuolating cytotoxin A