# References

AlMalki AS. 2008. Helicobacter pylori eradication in nonulcer dyspepsia: Does it really matter? Saudi J Gastroenterol. 14(2):93–95. 10.4103/1319-3767.39628 19568510
Anderson WF, Rabkin CS, Turner N, Fraumeni JF Jr, Rosenberg PS, Camargo MC. 2018. The changing face of noncardia gastric cancer incidence among US non-Hispanic whites. J Natl Cancer Inst. 110(6):1–8. 10.1093/jnci/djx262 29361173
Areia M, Carvalho R, Cadime AT, Rocha Goncalves F, Dinis-Ribeiro M. 2013. Screening for gastric cancer and surveillance of premalignant lesions: A systematic review of cost-effectiveness studies. Helicobacter. 18(5):325–337. 10.1111/hel.12050 23566268
Asaka M. 2014. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Chapter 1.2, Strategy to eliminate gastric cancer deaths in Japan; p. 21–27.
Aziz RK, Khalifa MM, Sharaf RR. 2015. Contaminated water as a source of Helicobacter pylori infection: A review. J Adv Res. 6(4):539–547. 10.1016/j.jare.2013.07.007 26199743
Balakrishnan M, George R, Sharma A, Graham DY. 2017. Changing trends in stomach cancer throughout the world. Curr Gastroenterol Rep. 19(8):36. 10.1007/s11894-017-0575-8 28730504
Biranjia-Hurdoyal SD, Seetulsingh-Goorah SP. 2016. Performances of four Helicobacter pylori serological detection kits using stool antigen test as gold standard. PLoS One. 11(10):e0163834. 10.1371/journal.pone.0163834 27736910
Bjorkman DJ.2017. Racial and ethnic disparities in gastric cancer risk. NEJM Journal Watch.https://production.jwatch.org/na43129/2017/01/17/racial-and-ethnic-disparities-gastric-cancer-risk. [Accessed on March 14, 2018]
Blase JL, Campbell PT, Gapstur SM, Pawlita M, Michel A, Waterboer T, Teras LR. 2016. Prediagnostic Helicobacter pylori antibodies and colorectal cancer risk in an elderly, Caucasian population. Helicobacter. 21(6):488–492. 10.1111/hel.12305 27006167
Bui D, Brown HE, Harris RB, Oren E. 2016. Serologic evidence for fecal-oral transmission of Helicobacter pylori. Am J Trop Med Hyg. 94(1):82–88. 10.4269/ajtmh.15-0297 26598563
Camargo MC, Yepez MC, Ceron C, Guerrero N, Bravo LE, Correa P, Fontham ET. 2004. Age at acquisition of Helicobacter pylori infection: Comparison of two areas with contrasting risk of gastric cancer. Helicobacter. 9(3):262–270. 10.1111/j.1083-4389.2004.00221.x 15165263
Canadian Cancer Society (CCS).2014. Helicobacter pylori (H. pylori). Canadian Cancer Society.https://www.cancer.ca/en/cancer-information. [Retrieved on July 30, 2014]
Cavaleiro-Pinto M, Peleteiro B, Lunet N, Barros H. 2011. Helicobacter pylori infection and gastric cardia cancer: Systematic review and meta-analysis. Cancer Causes Control. 22(3):375–387. 10.1007/s10552-010-9707-2 21184266
Centers for Disease Control and Prevention (CDC).2016. List of vaccines used in United States. Atlanta, GA: Centers for Disease Control and Prevention.https://www.cdc.gov/vaccines/vpd/vaccines-list.html. [Last updated: November 22, 2016]
Chen XZ, Schöttker B, Castro FA, Chen H, Zhang Y, Holleczek B, Brenner H. 2016. Association of Helicobacter pylori infection and chronic atrophic gastritis with risk of colonic, pancreatic and gastric cancer: A ten-year follow-up of the ESTHER cohort study. Oncotarget. 7(13):17182–17193. 10.18632/oncotarget.7946 26958813
Cheng HC, Wang JD, Chen WY, Chen CW, Chang SC, Sheu BS. 2015. Helicobacter pylori test-and-treat program can be cost-effective to prevent gastric cancer in Taiwanese adults: Referred to the nationwide reimbursement database. Helicobacter. 20(2):114–124. 10.1111/hel.12185 25382169
Chey WD, Leontiadis GI, Howden CW, Moss SF. 2017. ACG Clinical Guideline: Treatment of Helicobacter pylori infection. Am J Gastroenterol. 112(2):212–239. 10.1038/ajg.2016.563 28071659
Choi IJ. 2013. Current evidence of effects of Helicobacter pylori eradication on prevention of gastric cancer. Korean J Intern Med (Korean Assoc Intern Med). 28(5):525–537. 24009446
Choi IJ, Kook MC, Kim YI, Cho SJ, Lee JY, Kim CG, Park B, Nam BH. 2018. Helicobacter pylori therapy for the prevention of metachronous gastric cancer. N Engl J Med. 378(12):1085–1095. 10.1056/NEJMoa1708423 29562147
Choi IJ, Park JY, Herrero R. 2014 a. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Chapter 4.3, Effect of Helicobacter pylori eradication on gastric cancer prevention in the Republic of Korea: A randomized controlled clinical trial; p. 154–160.
Choi J, Kim SG, Yoon H, Im JP, Kim JS, Kim WH, Jung HC. 2014 b. Eradication of Helicobacter pylori after endoscopic resection of gastric tumors does not reduce incidence of metachronous gastric carcinoma. Clin Gastroenterol Hepatol. 12(5):793–800. 10.1016/j.cgh.2013.09.057 24100112
Coelho LG, Maguinilk I, Zaterka S, Parente JM, Passos MCF, Moraes-Filho JPP. 2013. 3rd Brazilian consensus on Helicobacter pylori. Arq Gastroenterol. 50(2):1–17. 10.1590/S0004-28032013005000001 23657298
Colquhoun A, Arnold M, Ferlay J, Goodman KJ, Forman D, Soerjomataram I. 2015. Global patterns of cardia and non-cardia gastric cancer incidence in 2012. Gut. 64(12):1881–1888. 10.1136/gutjnl-2014-308915 25748648
Conteduca V, Sansonno D, Lauletta G, Russi S, Ingravallo G, Dammacco F. 2013. H. pylori infection and gastric cancer: State of the art [review]. Int J Oncol. 42(1):5–18. 10.3892/ijo.2012.1701 23165522
Correa P, Fontham ET, Bravo JC, Bravo LE, Ruiz B, Zarama G, Realpe JL, Malcom GT, Li D, Johnson WD, et al. 2000. Chemoprevention of gastric dysplasia: Randomized trial of antioxidant supplements and anti-Helicobacter pylori therapy. J Natl Cancer Inst. 92(23):1881–1888. 10.1093/jnci/92.23.1881 11106679
Cover TL. 2016. Helicobacter pylori diversity and gastric cancer risk. MBio. 7(1):e01869–e01815. 10.1128/mBio.01869-15 26814181
de Martel C, Ferlay J, Franceschi S, Vignat J, Bray F, Forman D, Plummer M. 2012. Global burden of cancers attributable to infections in 2008: A review and synthetic analysis. Lancet Oncol. 13(6):607–615. 10.1016/S1470-2045(12)70137-7 22575588
de Sanjose S, Dickie A, Alvaro T, Romagosa V, Garcia Villanueva M, Domingo-Domenech E, Fernandez de Sevilla A, El-Omar E. 2004. Helicobacter pylori and malignant lymphoma in Spain. Cancer Epidemiol Biomarkers Prev. 13(6):944–948. 15184250
Derakhshan MH, Arnold M, Brewster DH, Going JJ, Mitchell DR, Forman D, McColl KE. 2016. Worldwide inverse association between gastric cancer and esophageal adenocarcinoma suggesting a common environmental factor exerting opposing effects. Am J Gastroenterol. 111(2):228–239. 10.1038/ajg.2015.405 26753891
Diaconu S, Predescu A, Moldoveanu A, Pop CS, Fierbinteanu-Braticevici C. 2017. Helicobacter pylori infection: Old and new. J Med Life. 10(2):112–117. 28616085
Doorakkers E, Lagergren J, Engstrand L, Brusselaers N. 2016. Eradication of Helicobacter pylori and gastric cancer: A systematic review and meta-analysis of cohort studies. J Natl Cancer Inst. 108(9). 10.1093/jnci/djw132 27416750
Dore MP, Pes GM, Bassotti G, Usai-Satta P.2016. Dyspepsia: When and how to test for Helicobacter pylori infection. Gastroenterol Res Pract. 2016:8463614. 10.1155/2016/8463614
Epplein M, Pawlita M, Michel A, Peek RM Jr, Cai Q, Blot WJ. 2013. Helicobacter pylori protein-specific antibodies and risk of colorectal cancer. Cancer Epidemiol Biomarkers Prev. 22(11):1964–1974. 10.1158/1055-9965.EPI-13-0702 24045925
Epplein M, Signorello LB, Zheng W, Peek RM Jr, Michel A, Williams SM, Pawlita M, Correa P, Cai Q, Blot WJ. 2011. Race, African ancestry, and Helicobacter pylori infection in a low-income United States population. Cancer Epidemiol Biomarkers Prev. 20(5):826–834. 10.1158/1055-9965.EPI-10-1258 21357376
Epplein M, Zheng W, Li H, Peek RM Jr, Correa P, Gao J, Michel A, Pawlita M, Cai Q, Xiang YB, et al. 2014. Diet, Helicobacter pylori strain-specific infection, and gastric cancer risk among Chinese men. Nutr Cancer. 66(4):550–557. 10.1080/01635581.2014.894096 24666234
Ferlay J, Soerjomataram I, Ervik M, Dikshit R, Eser S, Mathers C, Rebelo M, Parkin DM, Forman D, Bray F.2013. GLOBOCAN 2012 v1.0, cancer incidence and mortality worldwide: IARC CancerBase No. 11 [Internet]. Lyon, France: International Agency for Research on Cancer (IARC).http://globocan.iarc.fr.
Fernández de Larrea-Baz N, Michel A, Romero B, Pérez-Gómez B, Moreno V, Martín V, Dierssen-Sotos T, Jiménez-Moleón JJ, Castilla J, Tardón A, et al. 2017. Helicobacter pylori antibody reactivities and colorectal cancer risk in a case-control study in Spain. Front Microbiol. 8:888. 10.3389/fmicb.2017.00888 28611733
Ferreccio C. 2014. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Chapter 1.4, The regional status of current or planned gastric cancer prevention strategies in Latin America; p. 37–43.
Figura N, Marano L, Moretti E, Ponzetto A. 2016. Helicobacter pylori infection and gastric carcinoma: Not all the strains and patients are alike. World J Gastrointest Oncol. 8(1):40–54. 10.4251/wjgo.v8.i1.40 26798436
Fischbach W. 2014. Gastric MALT lymphoma - update on diagnosis and treatment. Best Pract Res Clin Gastroenterol. 28(6):1069–1077. 10.1016/j.bpg.2014.09.006 25439072
Fitzmaurice C, Allen C, Barber RM, Barregard L, Bhutta ZA, Brenner H, Dicker DJ, Chimed-Orchir O, Dandona R, Dandona L, et al. 2017. Global, regional, and national cancer incidence, mortality, years of life lost, years lived with disability, and disability-adjusted life-years for 32 cancer groups, 1990 to 2015: A systematic analysis for the Global Burden of Disease Study. JAMA Oncol. 3(4):524–548. 10.1001/jamaoncol.2016.5688 27918777
Ford AC, Forman D, Hunt RH, Yuan Y, Moayyedi P. 2014. Helicobacter pylori eradication therapy to prevent gastric cancer in healthy asymptomatic infected individuals: Systematic review and meta-analysis of randomised controlled trials. BMJ. 348:g3174. 10.1136/bmj.g3174 24846275
Forman D, Sierra M. 2014. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Introduction. The current and projected global burden of gastric cancer; p. 5–15.
Franco AT, Israel DA, Washington MK, Krishna U, Fox JG, Rogers AB, Neish AS, Collier-Hyams L, Perez-Perez GI, Hatakeyama M, et al. 2005. Activation of beta-catenin by carcinogenic Helicobacter pylori. Proc Natl Acad Sci USA. 102(30):10646–10651. 10.1073/pnas.0504927102 16027366
Franco AT, Johnston E, Krishna U, Yamaoka Y, Israel DA, Nagy TA, Wroblewski LE, Piazuelo MB, Correa P, Peek RM Jr. 2008. Regulation of gastric carcinogenesis by Helicobacter pylori virulence factors. Cancer Res. 68(2):379–387. 10.1158/0008-5472.CAN-07-0824 18199531
Fukase K, Kato M, Kikuchi S, Inoue K, Uemura N, Okamoto S, Terao S, Amagai K, Hayashi S, Asaka M, et al. 2008. Effect of eradication of Helicobacter pylori on incidence of metachronous gastric carcinoma after endoscopic resection of early gastric cancer: An open-label, randomised controlled trial. Lancet. 372(9636):392–397. 10.1016/S0140-6736(08)61159-9 18675689
Fukui T, Okazaki K, Tamaki H, Kawasaki K, Matsuura M, Asada M, Nishi T, Uchida K, Iwano M, Ohana M, et al. 2004. Immunogenetic analysis of gastric MALT lymphoma-like lesions induced by Helicobacter pylori infection in neonatally thymectomized mice. Lab Invest. 84(4):485–492. 10.1038/labinvest.3700056 14968120
Gawin A, Wex T, Lawniczak M, Malfertheiner P, Starzynska T. 2012. [Helicobacter pylori infection in pancreatic cancer]. Pol Merkuriusz Lek. 32(188):103–107.
Gisbert JP, Greenberg ER. 2014. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Chapter 3.2, Potential regimens for the mass eradication of Helicobacter pylori infection; p. 95–110.
González CA, Megraud F, Buissonniere A, Lujan Barroso L, Agudo A, Duell EJ, Boutron-Ruault MC, Clavel-Chapelon F, Palli D, Krogh V, et al. 2012. Helicobacter pylori infection assessed by ELISA and by immunoblot and noncardia gastric cancer risk in a prospective study: The Eurgast-EPIC project. Ann Oncol. 23(5):1320–1324. 10.1093/annonc/mdr384 21917738
Graham DY. 2015. Helicobacter pylori update: Gastric cancer, reliable therapy, and possible benefits. Gastroenterology. 148(4):719–731. 10.1053/j.gastro.2015.01.040 25655557
Helicobacter Cancer Collaborative Group. 2001. Gastric cancer and Helicobacter pylori: A combined analysis of 12 case control studies nested within prospective cohorts. Gut. 49(3):347–353. 10.1136/gut.49.3.347 11511555
Hernández DBP, Sabogal IAR, Arenas JDT. 2014. Efficacy of eradicating Helicobacter pylori for prevention of gastric cancer: Systematic review and meta-analysis. Rev Colomb Gastroenterol. 29(3):262–269.
Herrero R, Park JY, Forman D. 2014. The fight against gastric cancer - the IARC Working Group report. Best Pract Res Clin Gastroenterol. 28(6):1107–1114. 10.1016/j.bpg.2014.10.003 25439075
Hooi JKY, Lai WY, Ng WK, Suen MMY, Underwood FE, Tanyingoh D, Malfertheiner P, Graham DY, Wong VWS, Wu JCY, et al. 2017. Global prevalence of Helicobacter pylori infection: Systematic review and meta-analysis. Gastroenterology. 153(2):420–429. 10.1053/j.gastro.2017.04.022 28456631
Hsu WY, Lin CH, Lin CC, Sung FC, Hsu CP, Kao CH. 2014. The relationship between Helicobacter pylori and cancer risk. Eur J Intern Med. 25(3):235–240. 10.1016/j.ejim.2014.01.009 24485950
Hu Y, Wan JH, Li XY, Zhu Y, Graham DY, Lu NH. 2017. Systematic review with meta-analysis: The global recurrence rate of Helicobacter pylori. Aliment Pharmacol Ther. 46(9):773–779. 10.1111/apt.14319 28892184
Huang J, Zagai U, Hallmans G, Nyrén O, Engstrand L, Stolzenberg-Solomon R, Duell EJ, Overvad K, Katzke VA, Kaaks R, et al. 2017. Helicobacter pylori infection, chronic corpus atrophic gastritis and pancreatic cancer risk in the European Prospective Investigation into Cancer and Nutrition (EPIC) cohort: A nested case-control study. Int J Cancer. 140(8):1727–1735. 10.1002/ijc.30590 28032715
Huang JQ, Zheng GF, Sumanac K, Irvine EJ, Hunt RH. 2003. Meta-analysis of the relationship between cagA seropositivity and gastric cancer. Gastroenterology. 125(6):1636–1644. 10.1053/j.gastro.2003.08.033 14724815
International Agency for Research on Cancer (IARC). 2012. Biological Agents. Lyon, France: International Agency for Research on Cancer; Helicobacter pylori; p. 365–435.
International Agency for Research on Cancer (IARC). 2014. Helicobacter pylori eradication as a strategy for preventing gastric cancer. Vol. 8. Lyon, France: International Agency for Research on Cancer. IARC Working Group.
Ishaq S, Nunn L. 2015. Helicobacter pylori and gastric cancer: A state of the art review. Gastroenterol Hepatol Bed Bench. 8 Suppl 1:S6–S14. 26171139
Jones NL, Koletzko S, Goodman K, Bontems P, Cadranel S, Casswall T, Czinn S, Gold BD, Guarner J, Elitsur Y, et al. 2017. Joint ESPGHAN/NASPGHAN guidelines for the management of Helicobacter pylori in children and adolescents (Update 2016). J Pediatr Gastroenterol Nutr. 64(6):991–1003. 10.1097/MPG.0000000000001594 28541262
Kato S, Tachikawa T, Ozawa K, Konno M, Okuda M, Fujisawa T, Nakazato Y, Tajiri H, Iinuma K. 2001. Urine-based enzyme-linked immunosorbent assay for the detection of Helicobacter pylori infection in children. Pediatrics. 107(6):E87. 10.1542/peds.107.6.e87 11389285
Khalifa MM, Sharaf RR, Aziz RK. 2010. Helicobacter pylori: A poor man’s gut pathogen? Gut Pathog. 2(1):2. 10.1186/1757-4749-2-2 20356368
Krueger WS, Hilborn ED, Converse RR, Wade TJ. 2015. Environmental risk factors associated with Helicobacter pylori seroprevalence in the United States: A cross-sectional analysis of NHANES data. Epidemiol Infect. 143(12):2520–2531. 10.1017/S0950268814003938 25592266
Lansdorp-Vogelaar I, Sharp L. 2013. Cost-effectiveness of screening and treating Helicobacter pylori for gastric cancer prevention. Best Pract Res Clin Gastroenterol. 27(6):933–947. 10.1016/j.bpg.2013.09.005 24182612
Lee CW, Rickman B, Rogers AB, Ge Z, Wang TC, Fox JG. 2008. Helicobacter pylori eradication prevents progression of gastric cancer in hypergastrinemic INS-GAS mice. Cancer Res. 68(9):3540–3548. 10.1158/0008-5472.CAN-07-6786 18441088
Lee SY. 2014 a. Current progress toward eradicating Helicobacter pylori in East Asian countries: Differences in the 2013 revised guidelines between China, Japan, and South Korea. World J Gastroenterol. 20(6):1493–1502. 10.3748/wjg.v20.i6.1493 24587624
Lee YC. 2014 b. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Chapter 1.3, The regional status of current or planned gastric cancer prevention strategies in Taiwan, China; p. 28–36.
Lee YC, Chen TH, Chiu HM, Shun CT, Chiang H, Liu TY, Wu MS, Lin JT. 2013. The benefit of mass eradication of Helicobacter pylori infection: A community-based study of gastric cancer prevention. Gut. 62(5):676–682. 10.1136/gutjnl-2012-302240 22698649
Lee YC, Chiang TH, Chou CK, Tu YK, Liao WC, Wu MS, Graham DY. 2016. Association between Helicobacter pylori eradication and gastric cancer incidence: A systematic review and meta-analysis. Gastroenterology. 150(5):1113–1124. 10.1053/j.gastro.2016.01.028 26836587
Lee YC, Lin JT. 2017. Screening and treating Helicobacter pylori infection for gastric cancer prevention on the population level. J Gastroenterol Hepatol. 32(6):1160–1169. 10.1111/jgh.13726 28087975
Lee YC, Lin JT, Wu HM, Liu TY, Yen MF, Chiu HM, Wang HP, Wu MS, Hsiu-Hsi Chen T. 2007. Cost-effectiveness analysis between primary and secondary preventive strategies for gastric cancer. Cancer Epidemiol Biomarkers Prev. 16(5):875–885. 10.1158/1055-9965.EPI-06-0758 17507609
Leja M, Axon A, Brenner H. 2016. Epidemiology of Helicobacter pylori infection. Helicobacter. 21 Suppl 1:3–7. 10.1111/hel.12332 27531531
Leja M, Park JY, Murillo R, Liepniece-Karele I, Isajevs S, Kikuste I, Rudzite D, Krike P, Parshutin S, Polaka I, et al. 2017. Multicentric randomised study of Helicobacter pylori eradication and pepsinogen testing for prevention of gastric cancer mortality: The GISTAR study. BMJ Open. 7(8):e016999. 10.1136/bmjopen-2017-016999 28801429
Leja M, Park YY, Plummer M, Herrero R. 2014. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Chapter 4.2, Multicentre randomized study of Helicobacter pylori eradication and pepsinogen testing for prevention of gastric cancer mortality (gastric cancer prevention study by predicting atrophic gastritis; GISTAR); p. 147–153.
Leung WK, Lin SR, Ching JY, To KF, Ng EK, Chan FK, Lau JY, Sung JJ. 2004. Factors predicting progression of gastric intestinal metaplasia: Results of a randomised trial on Helicobacter pylori eradication. Gut. 53(9):1244–1249. 10.1136/gut.2003.034629 15306578
Li Q, Liu J, Gong Y, Yuan Y. 2017. Association of CagA EPIYA-D or EPIYA-C phosphorylation sites with peptic ulcer and gastric cancer risks: A meta-analysis. Medicine (Baltimore). 96(17):e6620. 10.1097/MD.0000000000006620 28445260
Li WQ, Ma JL, Zhang L, Brown LM, Li JY, Shen L, Pan KF, Liu WD, Hu Y, Han ZX, et al. 2014. Effects of Helicobacter pylori treatment on gastric cancer incidence and mortality in subgroups. J Natl Cancer Inst. 106(7). 10.1093/jnci/dju116 24925350
Limburg PJ, Stolzenberg-Solomon RZ, Colbert LH, Perez-Perez GI, Blaser MJ, Taylor PR, Virtamo J, Albanes D. 2002. Helicobacter pylori seropositivity and colorectal cancer risk: A prospective study of male smokers. Cancer Epidemiol Biomarkers Prev. 11(10 Pt 1):1095–1099. 12376513
Liu H, Merrell DS, Semino-Mora C, Goldman M, Rahman A, Mog S, Dubois A.2009. Diet synergistically affects Helicobacter pylori-induced gastric carcinogenesis in nonhuman primates. Gastroenterology. 137(4):1367-1379.e1361-1366. 10.1053/j.gastro.2009.07.041
Logan RP, Walker MM. 2001. ABC of the upper gastrointestinal tract: Epidemiology and diagnosis of Helicobacter pylori infection. BMJ. 323(7318):920–922. 10.1136/bmj.323.7318.920 11668141
Long Parma D, Muñoz E, Ogden SM, Westin GF, Leach RJ, Thompson IM, Ramirez AG. 2017. Helicobacter pylori infection in Texas Hispanic and non-Hispanic white men: Implications for gastric cancer risk disparities. Am J Men Health. 11(4):1039–1045. 10.1177/1557988317702038 28413904
Ma JL, Zhang L, Brown LM, Li JY, Shen L, Pan KF, Liu WD, Hu Y, Han ZX, Crystal-Mansour S, et al. 2012. Fifteen-year effects of Helicobacter pylori, garlic, and vitamin treatments on gastric cancer incidence and mortality. J Natl Cancer Inst. 104(6):488–492. 10.1093/jnci/djs003 22271764
Machida-Montani A, Sasazuki S, Inoue M, Natsukawa S, Shaura K, Koizumi Y, Kasuga Y, Hanaoka T, Tsugane S. 2007. Atrophic gastritis, Helicobacter pylori, and colorectal cancer risk: A case-control study. Helicobacter. 12(4):328–332. 10.1111/j.1523-5378.2007.00513.x 17669106
Maeda M, Moro H, Ushijima T. 2017. Mechanisms for the induction of gastric cancer by Helicobacter pylori infection: Aberrant DNA methylation pathway. Gastric Cancer. 20 Suppl 1:8–15. 10.1007/s10120-016-0650-0 27718135
Mahachai V, Vilaichone RK, Pittayanon R, Rojborwonwitaya J, Leelakusolvong S, Maneerattanaporn M, Chotivitayatarakorn P, Treeprasertsuk S, Kositchaiwat C, Pisespongsa P, et al. 2018. Helicobacter pylori management in ASEAN: The Bangkok consensus report. J Gastroenterol Hepatol. 33(1):37–56. 10.1111/jgh.13911 28762251
Malfertheiner P, Megraud F, O’Morain CA, Gisbert JP, Kuipers EJ, Axon AT, Bazzoli F, Gasbarrini A, Atherton J, Graham DY, et al. 2017. Management of Helicobacter pylori infection-the Maastricht V/Florence consensus report. Gut. 66(1):6–30. 10.1136/gutjnl-2016-312288 27707777
Malnick SD, Melzer E, Attali M, Duek G, Yahav J. 2014. Helicobacter pylori: Friend or foe? World J Gastroenterol. 20(27):8979–8985. 25083071
Mateos-Muñoz B, Pérez-de-la-Serna J, Ruiz-de-León A, Serrano-Falcón B, Casabona-Francés S, Velasco-Cerrudo A, Rey-Diaz-Rubio E. 2013. Enterohepatic Helicobacter other than Helicobacter pylori. Rev Esp Enferm Dig. 105(8):477–484. 10.4321/S1130-01082013000800006 24274445
Mera R, Fontham ET, Bravo LE, Bravo JC, Piazuelo MB, Camargo MC, Correa P. 2005. Long term follow up of patients treated for Helicobacter pylori infection. Gut. 54(11):1536–1540. 10.1136/gut.2005.072009 15985559
Mera RM, Bravo LE, Camargo MC, Bravo JC, Delgado AG, Romero-Gallo J, Yepez MC, Realpe JL, Schneider BG, Morgan DR, et al. 2017. Dynamics of Helicobacter pylori infection as a determinant of progression of gastric precancerous lesions: 16-year follow-up of an eradication trial. Gut. 67(7):1239–1246. 10.1136/gutjnl-2016-311685 28647684
Mitchell H, English DR, Elliott F, Gengos M, Barrett JH, Giles GG, Forman D. 2008. Immunoblotting using multiple antigens is essential to demonstrate the true risk of Helicobacter pylori infection for gastric cancer. Aliment Pharmacol Ther. 28(7):903–910. 18624791
Moayyedi P. 2014. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Chapter 3.3, Feasibility and cost–effectiveness of population-based Helicobacter pylori eradication; p. 111–121.
Morgan DR, Torres J, Sexton R, Herrero R, Salazar-Martínez E, Greenberg ER, Bravo LE, Dominguez RL, Ferreccio C, Lazcano-Ponce EC, et al. 2013. Risk of recurrent Helicobacter pylori infection 1 year after initial eradication therapy in 7 Latin American communities. JAMA. 309(6):578–586. 10.1001/jama.2013.311 23403682
National Toxicology Program (NTP). 2016. Draft report on carcinogens concept. Helicobacter pylori: Chronic infection. Research Triangle Park, NC: National Toxicology Program.
Nobel Prize.2005. Press release: Nobel Prize in Physiology or Medicine for 2005 awarded to Barry J. Marshall and J. Robin Warren. Nobel Media AB.https://www.nobelprize.org/nobel_prizes/medicine/laureates/2005/press.html. [Last updated: October 3, 2005]
Nozaki K, Shimizu N, Inada K, Tsukamoto T, Inoue M, Kumagai T, Sugiyama A, Mizoshita T, Kaminishi M, Tatematsu M. 2002. Synergistic promoting effects of Helicobacter pylori infection and high-salt diet on gastric carcinogenesis in Mongolian gerbils. Jpn J Cancer Res. 93(10):1083–1089. 10.1111/j.1349-7006.2002.tb01209.x 12417037
Ohata H, Kitauchi S, Yoshimura N, Mugitani K, Iwane M, Nakamura H, Yoshikawa A, Yanaoka K, Arii K, Tamai H, et al. 2004. Progression of chronic atrophic gastritis associated with Helicobacter pylori infection increases risk of gastric cancer. Int J Cancer. 109(1):138–143. 10.1002/ijc.11680 14735480
Pan KF, Zhang L, Gerhard M, Ma JL, Liu WD, Ulm K, Wang JX, Zhang L, Zhang Y, Bajbouj M, et al. 2016. A large randomised controlled intervention trial to prevent gastric cancer by eradication of Helicobacter pylori in Linqu County, China: Baseline results and factors affecting the eradication. Gut. 65(1):9–18. 10.1136/gutjnl-2015-309197 25986943
Park JB, Koo JS. 2014. Helicobacter pylori infection in gastric mucosa-associated lymphoid tissue lymphoma. World J Gastroenterol. 20(11):2751–2759. 10.3748/wjg.v20.i11.2751 24659867
Park JY, Forman D, Greenberg ER, Herrero R. 2013. Helicobacter pylori eradication in the prevention of gastric cancer: Are more trials needed? Curr Oncol Rep. 15(6):517–525. 10.1007/s11912-013-0341-5 24101366
Park JY, Nam BH, Herrero R, Choi IJ. 2017. Effect of Helicobacter pylori eradication on gastric cancer prevention in Korea: A randomized controlled clinical trial. In: Matsui S, Crowley J, editors. Frontiers of Biostatistical Methods and Applications in Clinical Oncology. Singapore: Springer; p. 315–330. 10.1007/978-981-10-0126-0_19
Parsonnet J. 2014. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Chapter 2.2, Are there benefits of Helicobacter pylori infection?; p. 72–79.
Parsonnet J, Hansen S, Rodriguez L, Gelb AB, Warnke RA, Jellum E, Orentreich N, Vogelman JH, Friedman GD. 1994. Helicobacter pylori infection and gastric lymphoma. N Engl J Med. 330(18):1267–1271. 10.1056/NEJM199405053301803 8145781
Pereira MI, Medeiros JA. 2014. Role of Helicobacter pylori in gastric mucosa-associated lymphoid tissue lymphomas. World J Gastroenterol. 20(3):684–698. 10.3748/wjg.v20.i3.684 24574742
Plummer M, Franceschi S, Vignat J, Forman D, de Martel C. 2015. Global burden of gastric cancer attributable to Helicobacter pylori. Int J Cancer. 136(2):487–490. 10.1002/ijc.28999 24889903
Raderer M, Wrba F, Kornek G, Maca T, Koller DY, Weinlaender G, Hejna M, Scheithauer W. 1998. Association between Helicobacter pylori infection and pancreatic cancer. Oncology. 55(1):16–19. 10.1159/000011830 9428370
Reynders MB, Miendje Deyi VY, Dahma H, Scheper T, Hanke M, Decolvenaer M, Dediste A. 2012. Performance of individual Helicobacter pylori antigens in the immunoblot-based detection of H. pylori infection. FEMS Immunol Med Microbiol. 64(3):352–363. 10.1111/j.1574-695X.2011.00920.x 22141752
Risch HA, Lu L, Kidd MS, Wang J, Zhang W, Ni Q, Gao YT, Yu H. 2014. Helicobacter pylori seropositivities and risk of pancreatic carcinoma. Cancer Epidemiol Biomarkers Prev. 23(1):172–178. 10.1158/1055-9965.EPI-13-0447 24234587
Risch HA, Yu H, Lu L, Kidd MS. 2010. ABO blood group, Helicobacter pylori seropositivity, and risk of pancreatic cancer: A case-control study. J Natl Cancer Inst. 102(7):502–505. 10.1093/jnci/djq007 20181960
Rokkas T, Sechopoulos P, Pistiolas D, Kothonas F, Margantinis G, Koukoulis G. 2013. The relationship of Helicobacter pylori infection and colon neoplasia, on the basis of meta-analysis. Eur J Gastroenterol Hepatol. 25(11):1286–1294. 10.1097/MEG.0b013e328363d3cd 23820245
Romero-Gallo J, Harris EJ, Krishna U, Washington MK, Perez-Perez GI, Peek RM Jr. 2008. Effect of Helicobacter pylori eradication on gastric carcinogenesis. Lab Invest. 88(3):328–336. 10.1038/labinvest.3700719 18180700
Sachs G, Scott DR, Wen Y. 2011. Gastric infection by Helicobacter pylori. Curr Gastroenterol Rep. 13(6):540–546. 10.1007/s11894-011-0226-4 21993716
Saito D, Boku N, Fujioka T, Fukuda Y, Matsushima Y, Sakaki N, Sato K, Sugiyama T, Takahashi S, Sato T, et al. 2005. Impact of H. pylori eradication on gastric cancer prevention: Endoscopic results of the Japanese intervention trial (JITHP-Study): A randomized multi-center trial. Gastroenterology. 128 Suppl 2:A4.
Schulte A, Pandeya N, Fawcett J, Fritschi L, Risch HA, Webb PM, Whiteman DC, Neale RE. 2015. Association between Helicobacter pylori and pancreatic cancer risk: A meta-analysis. Cancer Causes Control. 26(7):1027–1035. 10.1007/s10552-015-0595-3 25951801
Schulz TR, McBryde ES, Leder K, Biggs BA. 2014. Using stool antigen to screen for Helicobacter pylori in immigrants and refugees from high prevalence countries is relatively cost effective in reducing the burden of gastric cancer and peptic ulceration. PLoS One. 9(9):e108610. 10.1371/journal.pone.0108610 25268809
Servetas SL, Bridge DR, Merrell DS. 2016. Molecular mechanisms of gastric cancer initiation and progression by Helicobacter pylori. Curr Opin Infect Dis. 29(3):304–310. 10.1097/QCO.0000000000000248 26779778
Sheu BS, Wu MS, Chiu CT, Lo JC, Wu DC, Liou JM, Wu CY, Cheng HC, Lee YC, Hsu PI, et al. 2017. Consensus on the clinical management, screening-to-treat, and surveillance of Helicobacter pylori infection to improve gastric cancer control on a nationwide scale. Helicobacter. 22(3). 10.1111/hel.12368 28066960
Shimoyama T, Takahashi R, Abe D, Mizuki I, Endo T, Fukuda S. 2010. Serological analysis of Helicobacter hepaticus infection in patients with biliary and pancreatic diseases. J Gastroenterol Hepatol. 25 Suppl 1:S86–S89. 10.1111/j.1440-1746.2010.06224.x 20586873
Siao D, Somsouk M. 2014. Helicobacter pylori: Evidence-based review with a focus on immigrant populations. J Gen Intern Med. 29(3):520–528. 10.1007/s11606-013-2630-y 24065381
Simán JH, Engstrand L, Berglund G, Forsgren A, Florén CH. 2007. Helicobacter pylori and CagA seropositivity and its association with gastric and oesophageal carcinoma. Scand J Gastroenterol. 42(8):933–940. 10.1080/00365520601173863 17613922
Song ZQ, Zhou LY. 2015. Helicobacter pylori and gastric cancer: Clinical aspects. Chin Med J (Engl). 128(22):3101–3105. 10.4103/0366-6999.169107 26608993
Stolzenberg-Solomon RZ, Blaser MJ, Limburg PJ, Perez-Perez G, Taylor PR, Virtamo J, Albanes D. 2001. Helicobacter pylori seropositivity as a risk factor for pancreatic cancer. J Natl Cancer Inst. 93(12):937–941. 10.1093/jnci/93.12.937 11416115
Sugano K, Tack J, Kuipers EJ, Graham DY, El-Omar EM, Miura S, Haruma K, Asaka M, Uemura N, Malfertheiner P, et al. 2015. Kyoto global consensus report on Helicobacter pylori gastritis. Gut. 64(9):1353–1367. 10.1136/gutjnl-2015-309252 26187502
Suh M, Choi KS, Lee YY, Jun JK. 2013. Trends in cancer screening rates among Korean men and women: Results from the Korean National Cancer Screening Survey, 2004-2012. Cancer Res Treat. 45(2):86–94. 10.4143/crt.2013.45.2.86 23864841
Surveillance Epidemiology and End Results Program (SEER).2018. Cancer stat facts: Stomach cancer. Washington, DC: National Cancer Institute.https://seer.cancer.gov/statfacts/html/stomach.html.
Sutton P, Boag JM. 2018. Status of vaccine research and development for Helicobacter pylori. Vaccine. [ePub ahead of print]. 29627231
Taylor VM, Ko LK, Hwang JH, Sin MK, Inadomi JM. 2014. Gastric cancer in Asian American populations: A neglected health disparity. Asian Pac J Cancer Prev. 15(24):10565–10571. 10.7314/APJCP.2014.15.24.10565 25605140
Teng AM, Kvizhinadze G, Nair N, McLeod M, Wilson N, Blakely T. 2017. A screening program to test and treat for Helicobacter pylori infection: Cost-utility analysis by age, sex and ethnicity. BMC Infect Dis. 17(1):156. 10.1186/s12879-017-2259-2 28219322
Testerman TL, Morris J. 2014. Beyond the stomach: An updated view of Helicobacter pylori pathogenesis, diagnosis, and treatment. World J Gastroenterol. 20(36):12781–12808. 10.3748/wjg.v20.i36.12781 25278678
Thung I, Aramin H, Vavinskaya V, Gupta S, Park JY, Crowe SE, Valasek MA. 2016. Review article: The global emergence of Helicobacter pylori antibiotic resistance. Aliment Pharmacol Ther. 43(4):514–533. 10.1111/apt.13497 26694080
Torres J, Correa P, Herrero R, Piazuelo MB, Ferreccio C. 2016. Population-based strategies for Helicobacter pylori-associated disease management: Latin American perspective. In: Backert S, Yamaoka Y, editors. Helicobacter pylori Research: From Bench to Bedside. Springer Japan; p. 503–518. 10.1007/978-4-431-55936-8_22
U.S. Environmental Protection Agency (USEPA).2016. Contaminant Information Sheets (CISs) for the final fourth Contaminant Candidate List (CCL 4). Washington, DC: U.S. Environmental Protection Agency. EPA 815-R-16-003
U.S. Food and Drug Administration (FDA).2017. Vaccines licensed for use in the United States. U.S. Food and Drug Administration.https://www.fda.gov/BiologicsBloodVaccines/Vaccines/ApprovedProducts/ucm093833.htm. [Last accessed: December 7, 2017]
Wald NJ. 2014. Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer. Lyon, France: International Agency for Research on Cancer; Chapter 4.5, The treatment of Helicobacter pylori infection of the stomach in relation to the possible prevention of gastric cancer; p. 174–181.
Wang F, Sun MY, Shi SL, Lv ZS. 2014. Helicobacter pylori infection and normal colorectal mucosa-adenomatous polyp-adenocarcinoma sequence: A meta-analysis of 27 case-control studies. Colorectal Dis. 16(4):246–252. 10.1111/codi.12290 23692360
Wang MY, Liu XF, Gao XZ. 2015. Helicobacter pylori virulence factors in development of gastric carcinoma. Future Microbiol. 10(9):1505–1516. 10.2217/fmb.15.72 26346770
Wang X, Willén R, Svensson M, Ljungh A, Wadström T. 2003. Two-year follow-up of Helicobacter pylori infection in C57BL/6 and Balb/cA mice. APMIS. 111(4):514–522. 10.1034/j.1600-0463.2003.1110410.x 12780527
Wong BC, Lam SK, Wong WM, Chen JS, Zheng TT, Feng RE, Lai KC, Hu WH, Yuen ST, Leung SY, et al. 2004. Helicobacter pylori eradication to prevent gastric cancer in a high-risk region of China: A randomized controlled trial. JAMA. 291(2):187–194. 10.1001/jama.291.2.187 14722144
Wong BC, Zhang L, Ma JL, Pan KF, Li JY, Shen L, Liu WD, Feng GS, Zhang XD, Li J, et al. 2012. Effects of selective COX-2 inhibitor and Helicobacter pylori eradication on precancerous gastric lesions. Gut. 61(6):812–818. 10.1136/gutjnl-2011-300154 21917649
Wong IO, Schooling CM, Cowling BJ. 2014. Cost-effectiveness of Helicobacter pylori screening and treatment for gastric cancer in Hong Kong: A decision analytic approach. Hong Kong Med J. 20 Suppl 7:13–15. 25647818
Wu Q, Yang ZP, Xu P, Gao LC, Fan DM. 2013. Association between Helicobacter pylori infection and the risk of colorectal neoplasia: A systematic review and meta-analysis. Colorectal Dis. 15(7):e352–e364. 10.1111/codi.12284 23672575
Wündisch T, Dieckhoff P, Greene B, Thiede C, Wilhelm C, Stolte M, Neubauer A. 2012. Second cancers and residual disease in patients treated for gastric mucosa-associated lymphoid tissue lymphoma by Helicobacter pylori eradication and followed for 10 years. Gastroenterology. 143(4):936–942, quiz e913–e914. 10.1053/j.gastro.2012.06.035 22750463
Xie F, O’Reilly D, Ferrusi IL, Blackhouse G, Bowen JM, Tarride JE, Goeree R. 2009. Illustrating economic evaluation of diagnostic technologies: Comparing Helicobacter pylori screening strategies in prevention of gastric cancer in Canada. J Am Coll Radiol. 6(5):317–323. 10.1016/j.jacr.2009.01.022 19394572
Yamaoka Y, Graham DY. 2014. Helicobacter pylori virulence and cancer pathogenesis. Future Oncol. 10(8):1487–1500. 10.2217/fon.14.29 25052757
Yeh JM, Hur C, Ward Z, Schrag D, Goldie SJ. 2016. Gastric adenocarcinoma screening and prevention in the era of new biomarker and endoscopic technologies: A cost-effectiveness analysis. Gut. 65(4):563–574. 10.1136/gutjnl-2014-308588 25779597
Yeh JM, Kuntz KM, Ezzati M, Goldie SJ. 2009. Exploring the cost-effectiveness of Helicobacter pylori screening to prevent gastric cancer in China in anticipation of clinical trial results. Int J Cancer. 124(1):157–166. 10.1002/ijc.23864 18823009
Yoon SB, Park JM, Lim CH, Cho YK, Choi MG. 2014. Effect of Helicobacter pylori eradication on metachronous gastric cancer after endoscopic resection of gastric tumors: A meta-analysis. Helicobacter. 19(4):243–248. 10.1111/hel.12146 25056262
Yoshida T, Kato J, Inoue I, Yoshimura N, Deguchi H, Mukoubayashi C, Oka M, Watanabe M, Enomoto S, Niwa T, et al. 2014. Cancer development based on chronic active gastritis and resulting gastric atrophy as assessed by serum levels of pepsinogen and Helicobacter pylori antibody titer. Int J Cancer. 134(6):1445–1457. 10.1002/ijc.28470 24009139
You WC, Brown LM, Zhang L, Li JY, Jin ML, Chang YS, Ma JL, Pan KF, Liu WD, Hu Y, et al. 2006. Randomized double-blind factorial trial of three treatments to reduce the prevalence of precancerous gastric lesions. J Natl Cancer Inst. 98(14):974–983. 10.1093/jnci/djj264 16849680
Yu G, Murphy G, Michel A, Weinstein SJ, Männistö S, Albanes D, Pawlita M, Stolzenberg-Solomon RZ. 2013. Seropositivity to Helicobacter pylori and risk of pancreatic cancer. Cancer Epidemiol Biomarkers Prev. 22(12):2416–2419. 10.1158/1055-9965.EPI-13-0680 24089457
Zagari RM, Romano M, Ojetti V, Stockbrugger R, Gullini S, Annibale B, Farinati F, Ierardi E, Maconi G, Rugge M, et al. 2015. Guidelines for the management of Helicobacter pylori infection in Italy: The III working group consensus report 2015. Dig Liver Dis. 47(11):903–912. 10.1016/j.dld.2015.06.010 26253555
Zeng M, Mao XH, Li JX, Tong WD, Wang B, Zhang YJ, Guo G, Zhao ZJ, Li L, Wu DL, et al. 2015. Efficacy, safety, and immunogenicity of an oral recombinant Helicobacter pylori vaccine in children in China: A randomised, double-blind, placebo-controlled, phase 3 trial. Lancet. 386(10002):1457–1464. 10.1016/S0140-6736(15)60310-5 26142048
Zhang Y, Hoffmeister M, Weck MN, Chang-Claude J, Brenner H. 2012. Helicobacter pylori infection and colorectal cancer risk: Evidence from a large population-based case-control study in Germany. Am J Epidemiol. 175(5):441–450. 10.1093/aje/kwr331 22294430
Zhou L, Lin S, Ding S, Huang X, Jin Z, Cui R, Meng L, Li Y, Zhang L, Guo C, et al. 2014. Relationship of Helicobacter pylori eradication with gastric cancer and gastric mucosal histological changes: A 10-year follow-up study. Chin Med J (Engl). 127(8):1454–1458. 24762588
Zou QH, Li RQ. 2011. Helicobacter pylori in the oral cavity and gastric mucosa: A meta-analysis. J Oral Pathol Med. 40(4):317–324. 10.1111/j.1600-0714.2011.01006.x 21294774
Zullo A, Hassan C, Andriani A, Cristofari F, De Francesco V, Ierardi E, Tomao S, Morini S, Vaira D. 2009. Eradication therapy for Helicobacter pylori in patients with gastric MALT lymphoma: A pooled data analysis. Am J Gastroenterol. 104(8):1932–1937, quiz 1938. 10.1038/ajg.2009.314 19532131
Zullo A, Hassan C, Cristofari F, Andriani A, De Francesco V, Ierardi E, Tomao S, Stolte M, Morini S, Vaira D. 2010 a. Effects of Helicobacter pylori eradication on early stage gastric mucosa-associated lymphoid tissue lymphoma. Clin Gastroenterol Hepatol. 8(2):105–110. 10.1016/j.cgh.2009.07.017 19631287
Zullo A, Hassan C, Cristofari F, Perri F, Morini S. 2010 b. Gastric low-grade mucosal-associated lymphoid tissue-lymphoma: Helicobacter pylori and beyond. World J Gastrointest Oncol. 2(4):181–186. 10.4251/wjgo.v2.i4.181 21160595
Zumkeller N, Brenner H, Chang-Claude J, Hoffmeister M, Nieters A, Rothenbacher D. 2007. Helicobacter pylori infection, interleukin-1 gene polymorphisms and the risk of colorectal cancer: Evidence from a case-control study in Germany. Eur J Cancer. 43(8):1283–1289. 10.1016/j.ejca.2007.03.005 17446060