# 3. Prevention of H. pylori-associated Cancer

Stomach cancer is the fifth most common cancer worldwide, with around 1.3 million new cases occurring annually, and the third most common cause of death from cancer—it is estimated that over 800,000 people died of stomach cancer worldwide in 2015 (Fitzmaurice et al. 2017). An estimated 73% of all stomach-cancer cases are non-cardia gastric cancer (Colquhoun et al. 2015). Worldwide, 70% of all stomach-cancer cases occur in low-income countries. In low-risk areas, such as the United States, Europe, Australia, and New Zealand, the incidence of and mortality from stomach cancer show disparities, with minority, indigenous, and immigrant populations at higher risk (Balakrishnan et al. 2017; Epplein et al. 2011; SEER 2018; Taylor et al. 2014). In the United States, stomach cancer accounts for 1.7% of all new cancer cases, but some minority populations have a 40% to 50% higher risk (Bjorkman 2017; SEER 2018). In addition to disparities by geography and race, stomach-cancer incidence and mortality are higher in men than women; worldwide, the estimated age-standardized incidence rate in men is twice that in women (Forman and Sierra 2014; Herrero et al. 2014). Overall stomach-cancer incidence has decreased in recent years, by approximately 2% per year; however, recent evidence suggests it may be increasing in younger populations (Anderson et al. 2018). The estimated global burden of the disease is expected to increase in the next 10 to 15 years, primarily as a result of population growth and aging [Ferlay et al. (2013), as cited by IARC (2014)].

H. pylori infection has been established as a cause for non-cardia gastric cancer and gastric MALT lymphoma (IARC (2012); see Section 2) and may account for up to 6.2% of all cancer deaths worldwide (Plummer et al. 2015). Calculated population attributable fractions range from 75% to 89%, indicating that a large majority of these cancer cases could be avoided if H. pylori exposure were eliminated (de Martel et al. 2012; Plummer et al. 2015; Song and Zhou 2015).

This section provides an overview of the state of science for prevention of H. pylori-induced cancer, the cost-effectiveness of this prevention, issues and concerns for large-scale prevention programs, and current national and regional policies for stomach cancer prevention.

## 3.1 Prevention of H. pylori-induced Cancers: State of the Science

Screening and treatment of H. pylori-infected individuals show promise as a method for the prevention of stomach cancer. Over the past 20 years, numerous studies have been conducted on the effectiveness of screening and treatment methods. Three screening methods and two types of treatment have been evaluated (see Section 3.1.1). The benefits of H. pylori eradication have been evaluated in 10 randomized controlled trials and at least 16 cohorts. These studies support eradication of H. pylori for the prevention of stomach cancer, and recent meta-analyses have confirmed these findings (see Section 3.1.2). Moreover, several economic analyses have determined that screening and treatment of H. pylori is cost-effective as a prevention method (see Section 3.1.3). Several issues and concerns relevant to the implementation of large-scale eradication efforts must be taken into account. These include antibiotic resistance, the likelihood of H. pylori reinfection, the possible inverse relationship between H. pylori infection and some other gastric illnesses, the presence of atrophic damage at the time of eradication, and the need to tailor treatment programs to specific geographic regions (see Section 3.1.4).

Other methods of prevention of H. pylori-induced cancer include preventing the spread of H. pylori and developing a vaccine (see Section 2 for a discussion on the spread of H. pylori).

### 3.1.1 Screening for and Treatment of H. pylori Infection

H. pylori screening and treatment have been identified as candidates for population-level intervention programs in high-prevalence areas, supported by several cost-benefit analyses; however, additional data are needed. Several methods exist for H. pylori population screening, including serology tests for H. pylori antibodies, a stool antigen test, and a urea breath test. Stool antigen and urea breath tests are more expensive and may be harder to implement at a population level. H. pylori serological tests (for antibodies) detect both past and present infections, and therefore are not useful for determining the efficacy of H. pylori treatment (Moayyedi 2014) (see Section 2 for more details on detection methods).

Treatment of H. pylori infection often can achieve a high rate of eradication. The most common treatment is a standard triple therapy, which includes a PPI, clarithromycin, and either amoxicillin or metronidazole antibiotics given for 1 to 2 weeks. This PPI triple therapy is relatively low-cost and widely available. Early reports suggested that this treatment resulted in eradication rates of over 90%; however, rates more recently have fallen well below 80%. In some locations in Europe, the eradication rate for the standard PPI triple therapy is as low as 25% to 60%. This variability in effectiveness is likely due to the rise in antibiotic resistance, specifically to clarithromycin. In many parts of the world, clarithromycin resistance is so high that the clarithromycin-based PPI triple therapy is not recommended as the first-line treatment. Methods to improve the effectiveness of the PPI triple therapy have been proposed, such as increasing the dose by increasing the frequency of treatment, using second-generation PPIs, or increasing treatment duration [reviewed by Gisbert and Greenberg (2014)]. Another treatment currently recommended as a first-line therapy (concomitant therapy) adds metronidazole or nitroimidazole to the standard PPI treatment (Chey et al. 2017).

Another low-cost therapy (bismuth-containing quadruple therapy) combines bismuth salts, tetracycline, a PPI, and metronidazole for 14 days, with a reported eradication rate of over 80% to 90%. Bismuth-containing quadruple therapy is now recommended as the first-line treatment in areas of high clarithromycin resistance, while standard PPI triple therapy may be used in areas of low resistance. Although metronidazole resistance is high worldwide, the clinical impact of this resistance is low, and the quadruple therapy is effective when dose and duration are increased. Additional studies are needed on the effectiveness of bismuth-containing quadruple therapy as a first-line treatment. The unavailability of bismuth and tetracycline in many areas also must be considered for any population-level intervention programs. Because antibiotic resistance varies within populations, programs should use treatment regimens that have proven reliably effective in the target population and area, or methods based on the observed pattern of resistance [reviewed by Gisbert and Greenberg (2014) and Herrero et al. (2014)].

### 3.1.2 Efficacy and Effectiveness of H. pylori Eradication in Preventing Stomach Cancer

#### Gastric Cancer

Since 1997, a number of cohort studies and randomized controlled trials have been conducted to determine the efficacy and effectiveness of H. pylori eradication therapy in preventing gastric cancer. These studies looked at the effectiveness of eradication among individuals who had never had stomach cancer (primary prevention) and among patients with previous endoscopic resection of early gastric cancer (secondary prevention, sometimes referred to as tertiary prevention). The cohort studies were generally conducted in Japan and Korea, with one study each in Taiwan and Finland, and enrolled between 50 and 8,000 participants, with follow-up times ranging from 2 to 10 years.

Since 2000, six randomized controlled trials have investigated the primary prevention of gastric cancer following H. pylori eradication therapy. These trials have been primarily in China, with one each in Colombia (Correa et al. 2000) and Japan (Saito et al. 2005); follow-up times ranged from 3 to 14.7 years. An additional three trials, one in Japan (Fukase et al. 2008) and two in South Korea (Choi et al. 2018; Choi et al. 2014b), looked at the efficacy of H. pylori eradication for the secondary prevention of gastric cancer, with follow-up times of approximately 3 to 6 years.

Taken together, the nine trials demonstrated the partial effectiveness of H. pylori eradication therapy in reducing the incidence of gastric cancer. These studies generally had a large number of total participants, but many had small numbers of cases in both study arms. Only two of the nine studies had follow-up times exceeding 10 years, which may explain the lack of significant findings in several studies. Furthermore, all of these trials used the standard PPI triple therapy for eradication, and not the bismuth-containing quadruple therapy, which may be more effective in areas with high levels of clarithromycin resistance. Finally, all but one trial took place in eastern Asia, which may limit the generalizability of the results to other populations. The results of the randomized controlled trials are summarized in Table 3-1. Additional data will be provided by several ongoing trials, as well as long-term follow-up of the current studies. Additional data on prevention efficacy may provide additional support for large-scale eradication programs.

Table 3-1 Randomized Controlled Trials of H. pylori Eradication and the Incidence of Gastric Cancer

References Geographic Location | Study Population No. of Subjects^a^ Follow-up Duration | End Points | RR, HR, or OR (95% CI); No. of Cases^a^
Individuals without gastric cancer
Correa et al. (2000) Colombia^b^ | Asymptomatic men and women aged 29–69 with advanced gastric lesions (CAG, IM, and DYS); enrolled 1991 491/485 6 years | Gastric cancer IM regression IM progression | [1.48 (0.25–8.83); 3/2 cases]^c^ 3.1 (1.0–9.3) 0.4 (0.2–0.9)
Wong et al. (2004) China | Asymptomatic men and women aged 35–65 with mixed gastric lesions; enrolled 1994 817/813 7.5 years | Gastric cancer All subjects Baseline precancerous lesions No (62%) Yes (CAG, IM, DYS) | 0.63 (0.24–1.62); 7/11 p = 0.02; 0/6 p = 0.67; 7/5
Saito et al. (2005) Japan | Asymptomatic men and women aged 20–59 379/313 4 years | Gastric cancer | 0.55 (0.09–3.27); 2/3
Zhou et al. (2014) Leung et al. (2004) China | Asymptomatic men and women aged 35–75 with mixed gastric lesions; enrolled 1996 276/276 (2014); 295/292 (2004) 10 years (2014) 5 years (2004) | Gastric cancer 2014 (all) 2014 (no CAG) 2004 study IM progression 2014 2004 | [0.29 (0.06–1.36)]^d^; 2/7 0.00 (0.00–0.81); 0/6 [0.66 (0.18–2.36)]; 4/6 0.85 (0.78–0.92); NR 0.63 (0.43–0.93); 104/126
Ma et al. (2012) You et al. (2006) (7-year follow up) Li et al. (2014) (subgroup analyses) China | Asymptomatic men and women aged 35–64 with mixed gastric lesions; enrolled 1994–1995 (Shandong Intervention Trial) 1,130/1,128 14.7 years | All subjects Incidence Mortality Age ≥ 55 Incidence Mortality Baseline lesions Less severe (includes CAG) IM and DYS | 0.61 (0.39–0.96); 34/52 0.68 (0.36–1.29); 16/23 0.36 (0.17–0.79); 10/24 0.26 (0.09–0.79); 4/15 1.08 (0.31–3.81); 5/5 0.56 (0.34–0.91); 28/46
Wong et al. (2012) China | Asymptomatic men and women aged 35–64 with advanced gastric lesions (CAG or greater) enrolled 2002 255/285 4 years | Gastric cancer Regression Progression | [3.04 (0.32–28.99)]^e^; 3/1 2.19 (1.32–3.64); 96/82 1.08 (0.58–2.02); 30/50
Gastric cancer patients^f^
Fukase et al. (2008) Japan | Men and women aged 20–79 with early gastric cancer resection; enrolled 2001–2003 (secondary prevention) 272/272 3 years | Secondary gastric cancer | 0.35 (0.16–0.78); 9/24
Choi et al. (2014b) South Korea | Men and women aged 20–75 with early gastric cancer resection; enrolled 2005–2011 (secondary prevention) 444/457 2.6–93.3 months (Median = 38 months) | Secondary gastric cancer | [0.61 (0.28–1.31)]^d^; 10/17 (p = 0.15 by log rank)
Choi et al. (2018) South Korea | Men and women aged 18–75 with early gastric cancer resection; enrolled 2003–2013 (secondary prevention) 194/202 Median = 5.9 years, Maximum = 12.9 years | Secondary gastric cancer | 0.50 (0.26–0.94); 14/27 p = 0.03

CAG = chronic atrophic gastritis; DYS = dysplasia; HR = hazard ratio; IM = intestinal metaplasia; IRQ = interquartile range; OR = odds ratio; RR = relative risk.

^a^ Treatment/placebo.

^b^ Subjects were followed after the intervention, and patients in the placebo group were offered treatment (Mera et al. 2005; Mera et al. 2017).

^c^ Effect estimate calculated by Ford et al. (2014) meta-analysis.

^d^ Effect estimate calculated by Lee et al. (2016) meta-analysis.

^e^ Effect estimate calculated by Ford et al. (2014) meta-analysis. The authors did not evaluate gastric cancer, because seven of the nine cancer cases across several treatment groups occurred during the treatment period.

^f^ Patients with previous endoscopic resection of early gastric cancer.

The most informative studies were two large trials in China that evaluated primary prevention of gastric cancer. The Shandong Intervention Trial (Li et al. 2014; Ma et al. 2012; You et al. 2006) enrolled and randomized 2,258 H. pylori-seropositive subjects who were followed for 14.7 years, resulting in 34 cancer cases in the intervention group and 52 in the placebo group (OR = 0.61, 95% CI = 0.38 to 0.96). The next-largest trial, also conducted in China, enrolled 1,630 H. pylori-seropositive participants who were followed for 7.5 years. A total of 7 cancer cases were seen in the intervention group and 11 in the placebo group (HR = 0.63, 95% CI = 0.24 to 1.52) (Wong et al. 2004). These studies stratified by the type of gastric lesion at baseline but defined the lesion categories differently. The Shandong Intervention Trial grouped chronic atrophic gastritis with less severe lesions and found that H. pylori eradication was effective in preventing gastric cancer among participants with precancerous lesions (intestinal metaplasia and dysplasia) at baseline, but not among patients with less severe lesions; however, few cases of gastric cancer were seen in either treatment arm (intervention or placebo) among the patients with less severe lesions. In contrast, Wong et al. (2004) grouped chronic atrophic gastritis with the precancerous lesions and found that H. pylori eradication was effective only among patients with less severe lesions (see Table 3-1).

The additional four trials of primary prevention, two in China (Wong et al. 2012; Zhou et al. 2014) and one each in Colombia (Correa et al. 2000) and Japan (Saito et al. 2005), had a combined total of 10 gastric cancer cases in the intervention groups and 13 in the placebo groups. Two smaller studies lacked sufficient statistical power to evaluate gastric cancer incidence, but reported that H. pylori treatment was effective in promoting the regression of histological gastric lesions (Correa et al. 2000; Zhou et al. 2014). Wong et al. (2012) did not evaluate the effect of treatment on gastric cancer incidence, because seven of the nine cancer cases (across several treatment options, such as COX 2 inhibitor treatment) occurred during the treatment period.

When all six randomized controlled trials of primary prevention were included in a meta-analysis, the risk ratio was 0.66 (95% CI = 0.46 to 0.95), indicating a beneficial effect of H. pylori eradication therapy (Ford et al. 2014). It should be noted that these results were heavily weighted by the results in the Shandong Intervention Trial. Ford et al. (2014) also conducted a meta-analysis evaluating cancer mortality and found a non-statistically significant decrease in mortality in the intervention group (RR = 0.67, 95% CI = 0.40 to 1.11); the analysis included 24 deaths in the intervention groups and 36 in the placebo groups (Ford et al. 2014).

Three trials evaluating prevention of metachronous gastric cancer or “secondary prevention” (in Japan and South Korea) found a lower risk of new cancer in the H. pylori intervention group than in the control group (Choi et al. 2018; Choi et al. 2014b; Fukase et al. 2008). The findings were statistically significant in the Japanese study and in the Choi et al. (2018) study (see Table 3-1); additionally, when the results of the two earliest studies (Choi et al. 2014b; Fukase et al. 2008) were combined in a meta-analysis, a protective effect of eradication therapy was seen (RR = 0.47, 95% CI = 0.28 to 0.80) (Wald 2014).

Meta-analyses that pooled the results of cohort studies or of cohort studies and randomized controlled trials combined found results similar to those of the meta-analyses of the trials. An analysis of eight primary-prevention cohort studies reported a relative risk of 0.46 (95% CI = 0.32 to 0.66) (Doorakkers et al. 2016). A meta-analysis of both trials and cohort studies found relative risks of 0.62 (95% CI = 0.49 to 0.79) for primary prevention (six trials and eight cohorts) and 0.46 (95% CI = 0.35 to 0.60) for secondary prevention of metachronous gastric cancer (two trials and eight cohorts) (Lee et al. 2016). Another secondary-prevention meta-analysis (Yoon et al. 2014) found a relative risk of 0.42 (95% CI = 0.32 to 0.56) in a pooled analysis of 13 trials or cohort studies. Additional meta-analyses that combined both primary- and secondary-prevention studies (Chen et al. 2016; Hernández et al. 2014; Lee et al. 2016) were considered to be less informative. The results of these meta-analyses are summarized in Table 3-2. Other meta-analysis publications were identified but are not included in Table 3-2 because they included multiple publications of the same study in the analysis or included studies that did not evaluate efficacy or effectiveness in cancer prevention.

Table 3-2 Meta-analyses of Randomized Controlled Trials and Cohort Studies Investigating the Effectiveness of H. pylori Eradication in Reducing Gastric Cancer Incidence

Reference | Type of Study (No. of Studies) | Exposure Group (No. of Studies) | Risk Estimate | Heterogeneity
Studies on individuals without gastric cancer
Ford et al. (2014) | Trial (6) | Type of outcome Incidence (6) Mortality (3) Pre-neoplastic lesions present No (2) Yes (4) Mixed (2) | 0.66 (0.46–0.95) 0.67 (0.40–1.11) 0.42 (0.02–7.69) 0.86 (0.47–1.59) 0.38 (0.12–1.23) | I^2^ = 0%; p = 0.60 I^2^ = 0%; p = 0.90
Doorakkers et al. (2016) | Cohort (8) | Overall analysis Adjusted for follow-up and confounding (4) | 0.46 (0.32–0.66) 0.46 (0.29–0.72) | I^2^ = 32.3%; p = 0.17 I^2^ = 44.4%; p = 0.15
Studies on gastric cancer patients^a^
Yoon et al. (2014) ^b^ | Trial (2) Cohort (8) Other observational (2) | Trial and prospective cohort (3) | 0.39 (0.20–0.75) | I^2^ = 24.7%; p = 0.27 Outcome is metachronous gastric cancer
Combined studies of cancer and cancer-free patients
Chen et al. (2016) | Trial (8) | All studies Baseline diagnosis Non-atrophic gastritis/gastritis IM/DYS | 0.64 (0.48–0.85) 0.25 (0.08–0.81) 0.88 (0.59–1.31) | I^2^ = 32.3%; p = 0.93
Hernández et al. (2014) | Trial (7) | Overall five studies | 0.57 (0.42–0.79) | I^2^ = 0%; p = 0.48^c^
Lee et al. (2016) | Trial (8) Cohort (16) | All studies Trial Cohort Primary intervention Secondary intervention Baseline incidence of gastric cancer (tertiles) Lowest Middle Highest | 0.54 (0.46–0.65) 0.60 (0.44–0.81) 0.52 (0.41–0.64) 0.62 (0.49–0.79) 0.46 (0.35–0.60) 0.80 (0.56–1.15) 0.49 (0.38–0.64) 0.45 (0.32–0.64) | I^2^ = 0.0%; p = 0.67

CAG = chronic atrophic gastritis; DYS = dysplasia; IM = intestinal metaplasia.

^a^ Patients with previous endoscopic resection of early gastric cancer.

^b^ Because the meta-analysis of all studies included those that were not analytic studies, the results of that analysis are not included in the table.

^c^ Does not include Wong et al. (2012), Saito et al. (2005), or Choi et al. (2014b).

Several additional planned or ongoing studies will investigate the efficacy of H. pylori eradication in reducing the incidence of gastric cancer. A large-scale study in Baltic and Eastern European countries (the GISTAR study), which has recently begun recruitment, aims to recruit 30,000 men and women aged 40 to 64 and follow them for 15 years (Leja et al. 2017; Leja et al. 2014). A study in South Korea that has also recently begun recruitment plans to recruit 11,000 men and women aged 40 to 65 who are invited to participate in the national gastric cancer screening program. Those found to be infected with H. pylori will be randomized into the eradication study and followed for at least 10 years (Choi et al. 2014a; Park et al. 2017). A third ongoing study in the United Kingdom (the H. pylori Screening Study) recruited participants between 1997 and 2006. Although this is not an eradication study, those screened for H. pylori who tested positive were treated. All participants will be followed for 15 to 20 years (Wald 2014). Although not a placebo-controlled trial, a large study in China will compare a high-dose treatment with a low-dose treatment in 180,000 participants followed for at least 7 years. Initial eradication rates in the high-dose group were approximately 73% (Pan et al. 2016).

#### Gastric MALT Lymphoma

Because MALT lymphoma is a rare cancer, no randomized controlled trials have assessed the efficacy of H. pylori eradication therapy for its prevention and treatment; however, efficacy has been assessed in numerous observational studies. In a meta-analysis of 32 observational studies with 1,408 gastric MALT lymphoma patients, Zullo et al. (2009) found that H. pylori eradication treatment resulted in an overall remission rate of 77.5% (95% CI = 75.3% to 79.7%). Remission rates were higher for Stage 1 than Stage 2 lymphoma (75.3% vs. 55.6%), but treatment was effective at both cancer stages. Median follow-up times for these studies ranged from 1 to 5 years. Recently, long-term follow-up studies of gastric MALT lymphoma patients receiving H. pylori eradication therapy have shown remission in up to 80% of cases, with 80% of these individuals remaining disease-free after 10 years (Fischbach 2014; Wündisch et al. 2012).

### 3.1.3 Cost-benefit Analyses Studies

Numerous economic models in numerous geographic locations, including both low- and high-prevalence countries, have been published that evaluated whether H. pylori screening and treatment are cost-effective measures for the prevention of stomach cancer in a variety of populations. Two systematic reviews published in 2013 (Areia et al. 2013; Lansdorp-Vogelaar and Sharp 2013) reviewed 12 cost-effectiveness studies on H. pylori screening and treatment in the general population, including four studies each from North America, Europe, and Asia. Areia et al. (2013) also reviewed one South Korean cost-effectiveness study on H. pylori eradication after endoscopic removal of gastric cancer. The IARC working group on H. pylori eradication reviewed nine economic studies (Moayyedi 2014). Several new cost-effectiveness studies of screening and treatment have been published since these 2013 reviews. These newer studies were conducted in the United States (Yeh et al. 2016), Australia (Schulz et al. 2014), New Zealand (Teng et al. 2017), Taiwan (Cheng et al. 2015), and Hong Kong (Wong et al. 2014). Studies found H. pylori screening and treatment to be cost-effective based on a threshold of $50,000 per life-year saved, especially for high-risk populations. Importantly, the findings in many studies were robust to differences in H. pylori prevalence and patient gender and ethnicity (Lansdorp-Vogelaar and Sharp 2013). Most studies assumed 30% effectiveness of H. pylori eradication in reducing gastric cancer incidence; however, sensitivity analyses found that H. pylori eradication would still be cost-effective if the effectiveness of H. pylori eradication in reducing stomach cancer incidence were as low as 15% (Lansdorp-Vogelaar and Sharp 2013).

Factors that may influence the cost-effectiveness of H. pylori screening and treatment include screening methods, type of H. pylori therapy, and population characteristics such as age, race, or ethnicity, migrant status, and geographic region. Most general-population studies in both high- and low-prevalence countries evaluated serology screening (the most available test) and found it to be cost-effective [reviewed by Areia et al. (2013); Cheng et al. (2015); Lansdorp-Vogelaar and Sharp (2013); Teng et al. (2017); Wong et al. (2014); Yeh et al. (2016)]. However, some studies reported that the stool antigen screening method, which has greater sensitivity and specificity, was more cost-effective than either serology or urea breath test screening [Xie et al. (2009), as cited by Areia et al. (2013); Schulz et al. (2014)]. Most cost-effectiveness studies considered only the standard PPI triple therapy; however, one study evaluated the bismuth-containing quadruple therapy and found it to be cost-effective as well [Xie et al. (2009), as cited by Moayyedi (2014)].

Population characteristics were also considered in the economic models. The overall conclusion of Areia et al. (2013) was that screening at or above age 50 was the most cost-effective; however, several Asian studies concluded that screening beginning at age 30 would be the most cost-effective [Cheng et al. (2015); Lee et al. (2007); and Yeh et al. (2009), as cited by Areia et al. (2013)]. The effect of age may depend on the population; for example, Teng et al. (2017) found that cost-effectiveness was highest for Māori participants aged 45 to 49 and non-Māori participants aged 60 to 64. A study in Australia (Schulz et al. 2014) found screening and treatment of immigrants and refugees from high-prevalence countries to be cost-effective, and concluded that it may be an effective strategy for reducing stomach cancer in these populations.

In an overview of 10 cost-effectiveness or cost-utility studies, Lansdorp-Vogelaar and Sharp (2013) concluded H. pylori screening and treatment was cost-effective, coming in well below the threshold of $50,000 per life-year saved for the general population. In other, more recent, studies screening and treatment were found to be cost-effective only in populations at high-risk for gastric cancer, such as indigenous populations (Teng et al. 2017), or a subset of those at high risk, such as smokers (Yeh et al. 2016). In H. pylori high-prevalence countries, estimated costs ranged from $200 to $17,000 per life-year saved. The studies with the lowest assumed H. pylori prevalence had the highest cost per life-year saved, but eradication was still cost-effective. Likewise, studies reporting cost-effectiveness in low-prevalence countries also found screening and treatment to be cost-effective, ranging from $10,000 to $35,000 per life-year saved. While the cost-effectiveness estimates were, on average, higher in low-prevalence countries, they were still well below the threshold estimates (Lansdorp-Vogelaar and Sharp 2013).

In many of these studies, the cost-effectiveness threshold analyses considered only stomach cancer, and did not take into account the additional potential savings from H. pylori screening and treatment that could result from decreases in dyspepsia, ulcers, and other H. pylori-related disorders. The analyses also did not take into account the potential detrimental effects of increased antibiotic resistance or the potential reinfection rates, which have not been well studied (Hu et al. 2017; Lansdorp-Vogelaar and Sharp 2013). The IARC working group (IARC 2014) recommended that further studies should evaluate benefits using quality-adjusted life-years rather than life-years saved (Lansdorp-Vogelaar and Sharp 2013; Moayyedi 2014). Additional economic cost-benefit analyses are needed from randomized controlled trials, especially in areas where the eradication programs are most likely to be implemented first.

### 3.1.4 Issues and Concerns

Although the potential for H. pylori eradication to prevent 30% to 40% of new cases of non-cardia gastric cancer has been demonstrated, no large-scale H. pylori eradication programs have been implemented; however, a few smaller, targeted eradication programs have been implemented regionally (see Section 3.2.2). This caution is partially due to concern about unintended consequences of such programs. Three major concerns about H. pylori eradication are the potential for increased bacterial resistance to antibiotics, a negative impact on the normal gastrointestinal flora found in the body, and the likelihood of reinfection with H. pylori after treatment. These concerns are compounded by the fact that many of the antibiotics used to treat H. pylori infection are commonly used to treat other serious infections. A recent European consensus report cautioned that use of commonly used antibiotics could create additional resistance selection on pathogens other than H. pylori (Malfertheiner et al. 2017). In addition, evidence suggests an inverse relationship between H. pylori infection and GERD and its complications, including Barrett’s esophagus and esophageal adenocarcinoma [reviewed by Derakhshan et al. (2016); Parsonnet (2014)]. However, eradication does not appear to worsen pre-existing GERD (Zagari et al. 2015).

Reinfection with H. pylori has been observed to occur in more than 10% of those who were successfully treated in high prevalence areas, and reinfection rates increased as time since treatment increased (Hu et al. 2017; Morgan et al. 2013). In a recent review (Hu et al. 2017), reinfection rates ranged from 3.1% in countries with a very high human development index (HDI) to 11% in countries with a low HDI. Factors associated with reinfection included socioeconomic and sanitary conditions, as well as treatment adherence and study site, which was likely associated with regional antibiotic resistance, which suggests that recrudescence is a component of 1-year recurrence rates in many populations (Hu et al. 2017; Morgan et al. 2013).

Any eradication efforts should be tailored to the specific geographic area and target population, to guide the selection of appropriate antibiotic therapy and to develop better methods of treatment (Thung et al. 2016). All randomized controlled trials of eradication published to date were conducted in high-prevalence countries. However, both the short- and long-term effects of treatment programs will differ between regions with differing prevalence levels. Factors to consider in H. pylori eradication include the prevalence of H. pylori in the population, identification of the most appropriate population for screening (the general population or those showing symptoms of disease), the best age at which to begin screening, and the stage of disease at which eradication would be most effective. In high-prevalence regions, screening and treatment of the general population may be indicated, whereas in lower-prevalence countries with low-to-moderate risk of gastric cancer, integration of screening into existing prevention methods (such as colonoscopy screening) or screening those who show symptoms may be more effective (Lee et al. 2007). The optimal age for general screening and treatment programs may vary based on the prevalence of H. pylori in the population, and age should be taken into account (as discussed in Section 3.1.2).

The effectiveness of H. pylori eradication therapy in the prevention of stomach cancer may depend on the presence and severity of atrophic damage at the time of eradication (Sugano et al. 2015). H. pylori eradication therapy diminishes the inflammatory response and early treatment can help prevent the appearance of preneoplastic lesions. The optimal timing for stomach-cancer prevention may be before these preneoplastic conditions appear (Malfertheiner et al. 2017); however, H. pylori eradication may offer some benefits by reducing risk in the presence of preneoplastic conditions (Coelho et al. 2013; Malfertheiner et al. 2017). As mentioned in Section 3.1.2, the largest randomized controlled trial found that H. pylori eradication was effective in reducing cancer incidence among participants with precancerous lesions at baseline (Li et al. 2014).

## 3.2 Policies and Recommendations

Even though H. pylori is a treatable infection, and stomach cancer is one of the leading causes of cancer death worldwide, few national efforts at screening and prevention have been made (Section 3.2.2). There have been, however, numerous national and regional consensus statements on H. pylori screening and treatment in the prevention of H. pylori-induced cancer (Section 3.2.1).

### 3.2.1 National Consensus Recommendations for the Prevention of H. pylori-induced Cancer

Over the last 5 years, numerous publications have reported on national and regional consensus statements on H. pylori management. Typically, these statements are the result of a workshop of international, national, or regional experts who are charged with (1) reviewing the clinical and other relevant studies related to H. pylori management (e.g., diagnosis, treatment, and prevention) and (2) voting on the level of evidence (a grade reached according to specific guidelines) and the strength of recommendations for specific statements. Recommendations relevant to the prevention and treatment of H. pylori-induced cancer are summarized in Table 3-3. (Not included in the table are other recommendations, such as those for diagnosis and type of treatment.)

Table 3-3 Recommendations for Prevention of H. pylori-induced Cancer

Type of Recommendation | Population | Strength of the Association/Region | References
Screen and treat | General population | Strong: Should be considered for those under 35: Brazil (Third Brazilian Consensus) Insufficient: Chile (Chilean Society of Gastroenterology) Weak: Asia (10 ASEAN countries); Bangkok Report) (Community screening) | Coelho et al. (2013) Torres et al. (2016) Mahachai et al. (2018)
Screen and treat | Communities or individuals with a high risk of gastric cancer | Strong^a^: Europe (Maastricht V/Florence Consensus Report 20) Italy (II Working Group Consensus Report)^b^ Moderate^c^: Taiwan (Convened by the Steering Committee) Need more research: Chile | Malfertheiner et al. (2017) Zagari et al. (2015) Sheu et al. (2017) Torres et al. (2016)
Screen and treat | Populations with low and/or intermediate gastric cancer risk | Moderate^c^: Taiwan (intermediate risk only) Weak recommendation: Europe | Sheu et al. (2017) Malfertheiner et al. (2017)
Screen and treat | Individuals with family history of gastric cancer (e.g., first-degree relatives of gastric cancer patients) | Strong or recommended: 10 ASEAN countries, Italy^b^, Brazil, China (Chinese Society of Gastroenterology), South Korea (Korean College of Helicobacter and Upper Gastrointestinal Research Guideline Steering Committee) Insufficient: United States | Coelho et al. (2013); Lee (2014a); Mahachai et al. (2018); Zagari et al. (2015) Chey et al. (2017)
Screen and treat | Immigrants from high-risk regions | Recommended: Canada (Canadian Helicobacter Study Group and Canadian Cancer Society) | Taylor et al. (2014) [cites CCS (2014)]
Screen and treat | Patients with symptoms of gastric diseases | Strong or recommended: Italy, China, South Korea Moderate: Brazil Insufficient: United States | Lee (2014a); Zagari et al. (2015) Coelho et al. (2013) Chey et al. (2017)
Screen and treat | Patients with precancerous gastric lesions | Strong: 10 ASEAN countries Moderate: Brazil “Favors”: Chile Weak: South Korea | Mahachai et al. (2018) Coelho et al. (2013) Torres et al. (2016) Choi (2013)
Treatment of cancer | Patients with gastric MALT lymphoma | Strong or recommended: 10 ASEAN countries, Taiwan, China, South Korea, Japan, United States | Chey et al. (2017); Lee (2014a); Mahachai et al. (2018); Sheu et al. (2017)
Secondary prevention and/or treatment of cancer | Patients with gastric cancer | Strong or recommended: Italy, Chile, China, South Korea, Japan, United States | Chey et al. (2017); Lee (2014a); Torres et al. (2016); Zagari et al. (2015)

ASEAN = Association of Southeast Asian Nations. The 10 members are Brunei Darussalam, Cambodia, Indonesia, Laos, Malaysia, Myanmar, Philippines, Singapore, Thailand, and Vietnam.

^a^ Some reports referred to this as Group A recommendation.

^b^ Statement was “that the recommendation should be considered.”

^c^ Some reports referred to this as Group B recommendation.

Overall, there was consensus across the working groups that H. pylori eradication could reduce but not completely eliminate H. pylori-induced cancer. Most, but not all, working groups recommended screening and treatment programs for individuals with a high risk of non-cardia gastric cancer (including those with a family history of non-cardia gastric cancer or immigrants from high-risk regions); however, working groups from some countries (such as the United States and Chile) thought more research was needed. Some working groups recommended that screening and treatment programs include patients without advanced gastric lesions, and other groups (e.g., South Korea) recommended treatment of patients with intestinal metaplasia. Most groups recommended that the cancer-treatment program treat H. pylori among patients with gastric MALT lymphoma as well as non-cardia gastric cancer. One working group has recommended against general screening and treatment in children and adolescents; but it recommended that those with gastric or duodenal ulcers should be treated with a regimen tailored to the child or adolescent (Jones et al. 2017) The groups also recommended that endoscopic or histological surveillance may be needed after treatment (Lee et al. 2007; Sheu et al. 2017).

### 3.2.2 Screening and Treatment Programs

Worldwide, only a few countries have instituted gastric cancer prevention programs, either regionally or nationwide, and only some of these include H. pylori screening and treatment. The majority of these programs are in Asia. In Japan, which has high rates of stomach cancer, but also one of the highest 5-year survival rates, at 90% (Asaka 2014), an early stomach-cancer detection screening program using indirect barium contrast imaging has been in place for many years, although participation rates have been low. In 2013, after a successful trial showed that eradicating H. pylori reduced the incidence of secondary non-cardia gastric cancer, Japan approved national health insurance coverage of H. pylori eradication therapy for all patients with gastric MALT lymphoma, early non-cardia gastric cancer, idiopathic thrombocytopenia purpura, gastric and duodenal ulcers, and chronic gastritis, who are diagnosed via endoscopic examination. In South Korea, a national program was begun in the early 2000s to provide stomach-cancer screening every 2 years for all residents aged 40 and over. Participation rates have increased each year; in 2011, about half of those eligible were screened (Suh et al. 2013).

In 2006, Chile became the first Latin American country to institute a program that provides stomach-cancer screening to symptomatic people aged 40 and over. The program provides endoscopic examination for H. pylori detection, biopsy, and treatment (Ferreccio 2014). This program has had limited success, as population coverage has been small (Torres et al. 2016). The program is currently under review, and other strategies are being considered, including general-population screening and eradication in high-risk populations, accompanied by more efficient early-detection methods.

While most current gastric cancer prevention programs are symptoms based and include endoscopy or imaging as the primary screening for gastric cancer, several smaller scale efforts in Taiwan have included a general-population stomach-cancer prevention program combining H. pylori screening and endoscopy to older populations considered to be at highest risk for gastric cancer. The first program was pilot-tested on Matsu Island, a high-risk population, with promising results (Lee et al. 2013; Lee and Lin 2017). Based on these results, two additional regions of Taiwan have implemented a similar program combining the urea breath test for H. pylori and endoscopic screening for stomach cancer among those aged 50 to 69 (Lee 2014b). Another region in Taiwan is conducting a large-scale randomized controlled trial that combines colon-cancer screening with H. pylori screening, with treatment for those who test positive (Lee and Lin 2017).

## 3.3 Summary of the Recommendations of International Expert Working Groups (Including the IARC Working Group)

Given the strong link between H. pylori and non-cardia gastric cancer, as well as the high global burden of disease, international expert working groups have recommended that countries worldwide should devote additional public health resources to this disease. This global burden and the feasibility of treating the main cause of disease make H. pylori a possible target for intervention. Recent randomized trials have provided support for H. pylori eradication in the prevention of stomach cancer, while economic analyses have shown it to be cost-effective in many populations, particularly high-risk populations. Several additional large, randomized trials currently under way may add to the evidence. As well as preventing non-cardia gastric cancer (and gastric MALT lymphoma), H. pylori eradication may also prevent diseases such as dyspepsia and peptic ulcers, increasing its cost-effectiveness.

Although evidence for the effectiveness of screening and treatment in reducing stomach-cancer incidence is increasing, caution should be exercised in any planned intervention program. Local antibiotic resistance patterns should be taken into account in the choice of treatment method, as well as in targeting of the appropriate populations for intervention. Other potential consequences of eradication therapy must also be considered in any program, including increases in antibiotic resistance, changes in the natural gastrointestinal flora, and increases in diseases on which H. pylori may have a beneficial effect, such as GERD and esophageal cancer. Before implementation, any planned programs should consider objective assessments of feasibility, effectiveness, program acceptance, cost-effectiveness, and adverse consequences relevant to the local area.