# 2. Helicobacter pylori(Chronic Infection) Substance Profile

The substance profile provides a summary of the carcinogenicity information supporting NTP’s listing recommendation for Helicobacter pylori, together with information on biological properties, detection methods, human exposure, and regulations to limit exposure. The exposure information includes data on transmission and risk factors, non-cancer diseases, treatment, and prevention.

## 2.1 Biological Properties

H. pylori is a gram-negative, spiral- (or helical-) shaped, multi-flagellated bacterium that has infected humans for more than 58,000 years. It is a member of the family Helicobacteraceae, which includes over 24 Helicobacter species that colonize gastric or enterohepatic tissues (i.e., intestinal tract, biliary tree, and liver). Some gastric Helicobacter species from animals that can also infect humans include H. bizzozeroni, H. salomonis, H. felis, H. canadensis, and H. suis (IARC 2012). Some Helicobacter species that cause non-gastric diseases (primarily liver diseases) in humans include H. hepaticus, H. pullorum, and H. bilis (Mateos-Muñoz et al. 2013).

H. pylori colonizes the mucosal surface of the body (corpus) and the lower portion (antrum) of the stomach. Colonization involves an interaction between the proteins of the bacterium’s outer membrane and the epithelial cells of the stomach lining. One of the major H. pylori proteins involved in colonization is blood group antigen binding adhesin (BabA), which binds to blood group antigen A (IARC 2012). Although H. pylori triggers an immune response, the infected individual usually is unable to clear the infection; without treatment, an established infection usually lasts for the individual’s lifetime (Logan and Walker 2001; Testerman and Morris 2014).

All H. pylori strains produce the enzyme urease, which converts urea to ammonia and carbon dioxide, raising the pH (decreasing the acidity) of the surrounding area. A neutral pH environment thus is created in the mucosal layer adjacent to the surface epithelium of the stomach, allowing the bacterium to grow (Testerman and Morris 2014). Other properties of the bacterium also facilitate a persistent infection. Its helical shape and flagella help it to propel itself through the viscous mucosa, and a chemotaxis system (by which an organism moves in response to a chemical stimulus) helps the bacterium avoid the acidic stomach environment and stay closer to the surface epithelium. A non-toxic lipopolysaccharide component of the bacterium’s outer membrane may help reduce the infected individual’s inflammatory response to the infection. After antibiotic treatment, H. pylori can sometimes be detected in the upper part of the stomach (Sachs et al. 2011).

The H. pylori genome codes for several virulence factors, including cytotoxin-associated gene A product (CagA) and vacuolating cytotoxin A (VacA), which vary geographically and across strains (IARC 2012; Yamaoka and Graham 2014). Moreover, there are variants of H. pylori CagA producing strains, such as strains that differ in types or numbers of motifs, that are involved in binding to host targets and increased activities (i.e., EPIYA motifs). These variant strains have different geographical distributions (Cover 2016). Humans can be infected with several H. pylori strains, which may then exchange DNA, promoting the spread of virulence factors and antibiotic resistance (IARC 2012).

## 2.2 Detection

Numerous methods for diagnosing and screening for H. pylori infection are available, including assays to detect the bacterium itself, its DNA, antigens, antibodies, and urease activity (Table 2-1). The types of samples used in these tests range in invasiveness from biopsy samples taken during endoscopy, to blood samples, to collection of saliva, stool, urine, and expired air (Diaconu et al. 2017; Kato et al. 2001; Testerman and Morris 2014). These methods are summarized in the table below. Biopsy samples can also be evaluated for gastric pathology. All of these tests have moderate to high sensitivity (80% to 100%) and specificity (75% to 100%); however, sensitivity and specificity may vary depending on the condition of the patient, and some methods require several samples. Sensitivity and specificity may also vary by population under study (Biranjia-Hurdoyal and Seetulsingh-Goorah 2016). The method of detection used depends in part on the purpose of the testing (e.g., selection of treatment method or population studies), cost and technical skills, and patient considerations, such as age.

Table 2-1 Methods for Detection of H. pylori Infection

Test | Agent | Type of Sample | Comment
Histology: staining (e.g., Diff-Quik, Giemsa, hematoxylin and eosin) | H. pylori organism | Stomach tissue biopsy | Sensitivity: 93%–96% Specificity: 98%–99% Several samples needed; high cost; should be performed only on selected samples, such as from patients with gastritis or using certain types of antibiotics
Culture | H. pylori organism | Stomach tissue biopsy | Sensitivity: 80%–98% Specificity: ~100% Used for antimicrobial sensitivity testing; high cost
Rapid urease testing | H. pylori activity (active organisms) | Stomach tissue biopsy | Sensitivity: 88%–95% Specificity: 95%–~100%
Molecular methods (e.g., polymerase chain reaction) | H. pylori DNA or RNA | Stomach tissue biopsy; stool, saliva, or oral-cavity specimens | Sensitivity and specificity >95%
Serology testing using H. pylori antigens: enzyme-linked immunosorbent assay (ELISA), immunoblot | H. pylori antibodies (mainly immunoglobulin G [IgG]) | Serum or plasma | Sensitivity: 85%–96% Specificity: 75%–95% False-negative results can occur with underlying atrophic gastritis or gastric cancer or lifelong infections
Urea breath test | H. pylori urease activity (active infection) by measuring carbon dioxide (CO_2_) | Expired air | Sensitivity: 90%–99% Specificity: 88%–98%
Stool antigen test (e.g., ELISA, immunocards) | H. pylori antigens (active infection) | Stool | Sensitivity: 94% Specificity: 92% Recommended for children

Sources: Diaconu et al. (2017); Reynders et al. (2012); Testerman and Morris (2014).

Serological tests (such as ELISA or immunoblot) to detect H. pylori antibodies are widely available and relatively inexpensive. They are used in epidemiological and prevalence studies and are recommended for screening and treatment programs to prevent chronic disease (Areia et al. 2013). Serology tests are not recommended for low prevalence areas due to low specificity (Chey et al. 2017). Antibodies to H. pylori can persist for life, so these tests thus detect both past and current infections. An advantage of serological tests is that they are not affected by recent antibiotic use or acid-suppression therapy (Testerman and Morris 2014); however, they are not useful for measuring antibiotic treatment efficacy (Diaconu et al. 2017), as antibody titers are slow to fall. The sensitivity and specificity of serological tests depends on the antigens used in the assay, the type of assay (e.g., ELISA vs. immunoblot), the immunoglobulin class tested (mainly IgG, but also IgA), and factors that vary among infected individuals (González et al. 2012; Reynders et al. 2012). False-negative results can occur in individuals with advanced stomach diseases (e.g., atrophic gastritis) or cancer, because the bacteria are cleared from the mucosa of the stomach as the disease progresses. Case-control studies using ELISA may therefore underestimate the risk associated with H. pylori infection, because they will underestimate the prevalence in case but not control subjects (González et al. 2012; IARC 2012). Studies using immunoblot with multiple antigens have high sensitivity (95% to 96%) and specificity (93% to 96%) for detecting H. pylori infection (Mitchell et al. 2008; Simán et al. 2007).

## 2.3 Exposure

More than half of the world’s population, approximately 4.4 billion in 2015, are infected with H. pylori (Hooi et al. 2017). However, infection rates vary substantially within and among countries. In general, infection rates are related to socioeconomic status and levels of hygiene and are highest in low-income countries. Age-adjusted prevalence rates are particularly high (70% to 87%) in some countries in Africa, Latin America, the Caribbean, and Asia.

In the United States, approximately 30% to 36% of people are infected with H. pylori, the highest (ranging from 42% to up to 77%) prevalence being found among minority groups (e.g., the Alaskan indigenous population, Hispanics, and African Americans) and individuals born outside the United States, especially recent Asian immigrants (Hooi et al. 2017; Khalifa et al. 2010; Krueger et al. 2015; Siao and Somsouk 2014). The lowest prevalence is among non-Hispanic Whites with approximately 17% of people infected according to NHANES data (Krueger et al. 2015), although some more recent smaller studies report that this may be as low as 9% among Texans (Long Parma et al. 2017). Moreover, the prevalence of more virulent strains may be higher among minorities; for example, in a study of mostly low-income individuals in the southeastern United States, the risk of CagA-positive infection was higher among African-Americans than whites (Epplein et al. 2011).

The prevalence of H. pylori infection increases with increasing age (Krueger et al. 2015); however, the age of peak prevalence varies geographically with peak prevalence occurring at a younger age in lower income countries (50 years old) compared to higher income countries (over age 60). Geographical differences in H. pylori prevalence may be related, in part, to differences in the rate of acquisition early in life (Khalifa et al. 2010; Malnick et al. 2014). In low-income countries, initial infection often occurs in early childhood and chronic infection continues through adulthood. In contrast, in high-income countries, infection rates are low among young children and adolescents. The lower rate of infection among children may be due to the fact that prevalence rates in most of the world (e.g., especially the United States, Korea, and Japan) have decreased with each successive generation (referred to as the “birth cohort effect”) but have remained stable in many lower-income countries (such as in Latin and South America). The decline in H. pylori prevalence is related to access to clean water, improvements in sanitation, and improved household hygiene (Balakrishnan et al. 2017). Although there have been decreases in H. pylori infection in many countries, the prevalence remains high in adults.

Areas of high prevalence of H. pylori are not always directly correlated with high risk areas of gastric cancer, e.g., H. pylori prevalence but not gastric cancer incidence is high in Africa (Hooi et al. 2017). In a study in Colombia, two populations with different risks of stomach cancer (high and low) had similar prevalence patterns of H. pylori infection at an early age, suggesting that age of acquisition of infection may not play a major role in explaining gastric cancer risk (Camargo et al. 2004). Geographical differences in gastric cancer incidence may be explained in part by H. pylori genotypes, co-exposures (such as diet), and patients characteristics (for more information, see Carcinogenicity).

### 2.3.1 Transmission

Data from the U.S. National Health and Nutrition Examination Survey (NHANES) suggest that risk factors for H. pylori infection include age, race or ethnicity (minority), socioeconomic status (low family income and lower education level), and crowded housing (Krueger et al. 2015). Studies in other countries have also identified age, socioeconomic status, crowding, and poor sanitation as major risk factors and have suggested that gender and genetic predisposition also may influence H. pylori prevalence rates (Khalifa et al. 2010).

The bacterium is spread by person-to-person contact, especially among family members. This occurs primarily via oral-to-oral transmission and possibly via gastro-oral transmission mediated by refluxed gastric juice or fecal-oral transmission. H. pylori has been isolated from the oral cavity, gastric juices, and fecal samples (Khalifa et al. 2010). A meta-analysis of 22 studies found that H. pylori infection in the oral cavity was significantly more common among subjects with gastric H. pylori infection than among subjects without gastric H. pylori infection (Zou and Li 2011).

H. pylori can also be transmitted indirectly by drinking of contaminated water or possibly in food or from animal reservoirs (Aziz et al. 2015; Bui et al. 2016; IARC 2012; Khalifa et al. 2010). The bacterium has been detected in surface, ground, and well water in the United States and in treated municipal, tap, well, and bottled water in other countries (such as Peru and Sweden), and H. pylori can remain viable in chlorinated water [reviewed by Aziz et al. (2015); IARC (2012)]. The U.S. Environmental Protection Agency considers H. pylori a drinking-water contaminant and a candidate for possible regulatory action under the Safe Drinking Water Act (Krueger et al. 2015; USEPA 2016). Some epidemiological studies, including a study using NHANES data (for people aged 3 to 19) found that using well water or other unpurified water is a risk factor for H. pylori infection (Aziz et al. 2015; Khalifa et al. 2010; Krueger et al. 2015). In Japan, H. pylori prevalence was substantially lower in a cohort of individuals born between the 1960s and 1980s (14%) than in cohorts born between 1927 (54%) and 1949 (42%), which could be the result of improvements in sanitary conditions, such as the introduction of municipal water supply in the 1950s to 1970s (Leja et al. 2016). NHANES data also indicated that soil-related occupations among adults are a risk factor for H. pylori infection, which suggests an environmental route of transmission (Krueger et al. 2015). However, other factors (country of birth, childhood poverty/crowding, race-ethnicity) are most likely more important for transmission of H. pylori in the United States.

### 2.3.2 Diseases (Noncancer), Treatment, and Prevention

In 2005, the Nobel Prize in Physiology or Medicine was awarded to Barry Marshall and Robin Warren for their discovery that an infectious agent, H. pylori, causes gastritis and peptic ulcers (up to 80% of gastric ulcers and over 90% of duodenal ulcers) (Nobel Prize 2005). H. pylori infection is also associated with some non-stomach diseases, such as iron-deficiency anemia and immune thrombocytopenia purpura (a tendency to bleed easily because of reduced numbers of blood platelets), and may be associated with non-ulcer dyspepsia (indigestion), although this association is not clear (AlMalki 2008; Dore et al. 2016; Testerman and Morris 2014).

Many different therapies are used in the United States, but the American College of Gastroenterology’s Clinical Guideline for Treatment of H. pylori Infection update in 2017 (Chey et al. 2017) indicates that first-line regimens approved by the U.S. Food and Drug Administration (FDA) are either (1) clarithromycin triple therapy, with that antibiotic in combination with a proton-pump inhibitor (PPI) and a second antibiotic for 14 days, or (2) bismuth quadruple therapy, with a bismuth salt, a PPI, and two antibiotics for 10 to 14 days. Due to high levels of antibiotic resistance, clarithromycin triple therapy should only be considered a first line treatment in areas where resistance among H. pylori patients is known to be low. Eradication of H. pylori infection in an individual can be affected by (1) patient-related factors (e.g., adherence to the treatment regimen, smoking, diabetes, genetic factors influencing metabolism of PPIs, and past antibiotic use) and (2) H. pylori-related factors. The susceptibility of H. pylori to specific antibiotics is the most important determinant of successful H. pylori treatment, and patterns of resistance to specific antibiotics can vary geographically (Chey et al. 2017; Malfertheiner et al. 2017). If first-line treatment fails, second-line or salvage therapy generally is based on local antibiotic resistance rates (where known) and an individual’s previous antibiotic use. Globally, H. pylori eradication rates have declined as antibiotic resistance rates have increased (Thung et al. 2016). Currently, no H. pylori vaccine is available (CDC 2016; FDA 2017). Vaccine development efforts are ongoing, but no large scale vaccine efforts are taking place (Sutton and Boag 2018; Zeng et al. 2015).

Randomized controlled trials (clinical studies with control groups that receive placebos) have shown that screening and treatment of H. pylori reduces stomach-cancer risk by approximately 35% (Herrero et al. 2014; Park et al. 2013). Moreover, economic modeling studies, in both low- and high-prevalence countries, have shown that H. pylori eradication is cost-effective. However, effectiveness in reducing cancer risk depends on several factors, such as patient characteristics, screening methods, efficacy of H. pylori eradication, and the stage of H. pylori-associated gastric disease. H. pylori eradication may increase bacterial resistance to antibiotics, alter the normal gastrointestinal flora found in the body, and possibly increase the incidence of diseases for which H. pylori infection may offer protection, such as esophageal cancer and gastro-esophageal reflux disease (GERD). Numerous international and national working groups have recommended that planned programs should consider objective assessments of feasibility, effectiveness, program acceptance, cost-effectiveness, and adverse consequences relevant to the local area before implementation. (See Section 3 for more information on prevention strategies.)

## 2.4 Carcinogenicity

This section reviews the evidence for carcinogenicity in humans (Section 2.4.1) and experimental animals (Section 2.4.2) and mechanistic data (Section 2.4.3) that are key to NTP’s listing recommendation (Section 2.4.4).

### 2.4.1 Cancer Studies in Humans

Worldwide, stomach cancer is the fifth most common type of cancer and third leading cause of death from cancer, with most cases occurring in low- and middle-income countries. Adenocarcinoma accounts for over 90% to 95% of all stomach cancer (Balakrishnan et al. 2017), which can be broadly classified by the location in the stomach where the cancer develops: (1) cardia gastric cancer develops in the first portion of the stomach, closest to the esophagus, and (2) non-cardia gastric cancer develops in more distal parts of the stomach, closer to the small intestine. Gastric lymphoma, which consists primarily of gastric mucosa-associated lymphoid tissue (MALT) lymphoma and diffuse large B-cell lymphoma, accounts for approximately 2% to 8% of all stomach tumors (Park and Koo 2014; Zullo et al. 2010b). Gastric MALT lymphoma is a type of extranodal B-cell lymphoma (i.e., not arising in lymph nodes or other lymphoid tissue) that is low-grade, slow growing, and very rare (with a worldwide incidence of 1 to 1.5 cases per 100,000 people) (Pereira and Medeiros 2014).

#### Stomach Cancer

Evidence that H. pylori causes stomach (non-cardia gastric) cancer in humans is based on (1) consistent evidence from numerous epidemiological studies on stomach cancer, (2) a pooled analysis of 12 epidemiological studies, and (3) several meta-analyses (combined statistical analyses of the data from several different studies).

Cohort studies found that H. pylori-infected individuals were more likely to develop stomach cancer than were uninfected individuals (IARC 2012). These studies followed subjects with and without H. pylori infection for 4 to 10 years. Depending on the study, the subjects were either asymptomatic or had various types of stomach disease and were enrolled in various types of screening programs. Numerous nested case-control studies (case-control analyses conducted within cohorts of subjects), with follow-up times up to 15 years, provided evidence that the increased risk was specifically for non-cardia gastric cancer (IARC 2012). A pooled analysis of 12 of these nested case-control studies, which included 762 case subjects and 2,250 control subjects, matched to the case subjects by age, sex, and date of sample collection for H. pylori testing, found a risk factor of 2.97 (95% confidence interval [CI] = 2.34 to 3.77) for non-cardia gastric cancer and H. pylori infection (Helicobacter Cancer Collaborative Group 2001). The highest risk was for subjects followed for a longer time after enrollment (odds ratio [OR] = 5.93, 95% CI = 3.41 to 10.30 for ≥10 years of follow-up, compared with OR = 2.39, 95% CI = 1.82 to 3.12 for <10 years of follow-up).

Similar findings of an excess risk of non-cardia gastric cancer were reported in a meta-analysis of data from eight studies (Huang et al. 2003). Nested case-control studies that either were published after the 2001 pooled analysis or had accrued more cases since the 2001 pooled analysis also found significantly elevated risks for non-cardia gastric cancer, confirming the association with H. pylori infection.

Most epidemiological studies measured H. pylori infection status by the presence of antibodies to H. pylori (i.e., seropositivity). Higher risks for non-cardia gastric cancer (increased by over tenfold) were found when H. pylori seropositivity was measured by a more sensitive assay (immunoblot, rather than the ELISA method typically used) (González et al. 2012; Mitchell et al. 2008; Simán et al. 2007). In most studies that looked at infection with various strains of H. pylori, higher risks were found for infection with strains that produced CagA than for infection with CagA-negative strains. A meta-analysis of data on H. pylori-positive cases from nine studies found that CagA seropositivity approximately doubled the risk of non-cardia gastric cancer over that due to H. pylori infection alone (Huang et al. 2003). Some studies have evaluated gastric cancer risk for specific CagA variants (type and number of EPIYA motifs, see Properties); e.g., a single EPIYA-D motif was associated with increased gastric cancer in studies in Asia, whereas multiple EPIYA-C motifs were associated with increased gastric cancer risk in studies in the United States and Europe (Li et al. 2017).

Some studies found a higher risk of stomach cancer among H. pylori-infected individuals who smoked or who consumed salted, smoked, processed foods, or red meat, and a lower risk among those with diets high in vegetables or intake of vitamins, suggesting that these exposures (diet or types of food) may be co-factors for H. pylori-induced stomach cancer (Epplein et al. 2014; IARC 2012). Several studies controlled for known risk factors for stomach cancer, and increased risks were found in studies in various geographical locations, which increases confidence that the elevated risks observed in these studies are not explained by bias, chance, or confounding.

Evidence for a role of H. pylori in cardia gastric cancer is less clear and may be restricted to specific subtypes of cardia gastric cancer. Neither the Helicobacter Cancer Collaborative Group pooled analysis of nested case-control studies (274 cases and 827 controls) nor the meta-analysis by Huang et al. (2003) of 16 published studies found an excess risk of cardia gastric cancer and H. pylori infection. However, a meta-analysis of all types of studies (primarily case-control studies) found that H. pylori infection increased the risk of cardia gastric cancer in high-risk countries (adjusted relative risk [RR] = 1.59, 95% CI = 1.03 to 1.45; 11 studies) but not in low-risk countries (RR = 0.80, 95% CI = 0.63 to 1.02; 14 studies) (Cavaleiro-Pinto et al. 2011). The differences in the risk patterns might be due to different subtypes of cardia gastric cancer or inclusion of adenocarcinoma of the esophagus or the gastroesophageal junction with cardia gastric cancer; however, few studies have addressed these anatomical distinctions (Malfertheiner et al. 2017).

#### Gastric MALT Lymphoma

Evidence that H. pylori causes gastric MALT lymphoma comes primarily from 16 intervention (non-controlled) studies [as reviewed by IARC (2012)], which found that eradication of H. pylori infection in gastric MALT lymphoma patients resulted in high rates (62% to 100%) of complete remission of the cancer. A pooled analysis of patients with gastric MALT lymphoma from 32 studies found that remission occurred in approximately 78% of the patients who were cured of H. pylori infection (Zullo et al. 2010a). Because of the rarity of this cancer, the number of observations is limited. Two small case-control analyses (a prospective nested case-control study and a hospital-based case-control study) found a positive association between H. pylori infection and gastric MALT lymphoma, which provides additional support for a causal relationship [Parsonnet et al. (1994) and de Sanjose et al. (2004), as cited by IARC (2012)].

### 2.4.2 Cancer Studies in Experimental Animals

H. pylori infection (orally administered by gavage) caused malignant tumors in two different types of stomach tissue in rodents. Importantly, the types of cancer observed in animals infected with H. pylori—gastric tumors and gastric lymphoma—are similar to those linked with H. pylori infection in humans. Some of these animal models are thought to mimic tumor progression in humans, as they also show similar types of H. pylori-induced gastric lesions.

H. pylori infection increased the incidences of malignant stomach tumors (mainly adenocarcinoma and some carcinoid) (1) in Mongolian gerbils in some, but not all, studies and (2) in transgenic (genetically altered) mice. Differences in the findings in gerbils may be due to differences in the H. pylori strain, gerbil strain, dose, and/or duration of exposure. A gerbil-adapted strain of H. pylori (derived from a human gastric ulcer strain) increased the incidence of malignant stomach tumors in Mongolian gerbils as early as 8 to 12 weeks after infection [Franco et al. (2005); Franco et al. (2008); and Romero-Gallo et al. (2008), as cited by IARC (2012)]. In general, findings in gerbils infected with other H. pylori strains were mixed; positive findings were more common in studies of longer duration, conducted in Asia, or using higher doses. IARC (2012) noted that the genetic background of the Mongolian gerbils may have evolved differently among colonies established in different geographic locations and that the pathology grading varied among studies. H. pylori infection caused gastric carcinoma in several studies in INS-GAS transgenic mice, which have been genetically modified to produce more gastrin (a peptide that increases the secretion of gastric acid). In studies of other types of transgenic mice (TGF-β- or p27-deficient mice, which have increased susceptibility to carcinogens), H. pylori infection increased the incidence of combined gastric dysplasia (a precancerous lesion) and carcinoma (IARC 2012). Two studies, one in Mongolian gerbils [Romero-Gallo et al. (2008), as cited by IARC (2012)] and the other in transgenic mice [Lee et al. (2008), as cited by IARC (2012)], found that H. pylori eradication therapy, when given early, inhibited the development of malignant stomach tumors (adenocarcinoma), which increases confidence that H. pylori causes stomach cancer in experimental animals.

There is strong evidence that H. pylori given in combination with other carcinogens (N-methyl-N-nitrosourea [MNU], N-methyl-N′-nitro-N-nitrosoguanidine, or ethylnitronitrosoguanidine) increased the incidences of stomach tumors over those in rodents (IARC 2012) and non-human primates (Liu et al. 2009) exposed only to the other carcinogens. Early H. pylori eradication therapy reduced the incidence of stomach tumors (adenocarcinoma) induced by combined administration of H. pylori and MNU [Nozaki et al. (2002), as cited by IARC (2012)]. The addition of a high-salt diet also increased the incidence of stomach tumors in H. pylori-infected gerbils.

H. pylori infection caused gastric lymphoma in two different strains of inbred mice [Wang et al. (2003)[underlined: ,] as cited by IARC (2012)] and in neonatal mice that had had their thymus glands removed (Fukui et al. 2004). In the latter study, all of the mice developed gastric MALT lymphoma by the age of 12 months.

### 2.4.3 Mechanisms of Carcinogenesis and Other Relevant Data

The mechanisms by which H. pylori causes stomach cancer are complex and involve many different factors. They involve interactions between (1) direct effects of the toxic action of H. pylori virulence factors (e.g., the effects of CagA, VacA, and outer inflammatory protein), (2) indirect effects due to modification of the infected individual’s inflammatory responses to chronic H. pylori infection, which can be influenced by the genes regulating immune processes and by lifestyle and dietary habits, and (3) changes in acid secretion in the stomach. Collectively, this information may help to explain why only a small fraction of H. pylori-infected individuals (10% in high-risk countries and 1% to 3% in other countries) develop stomach cancer (Balakrishnan et al. 2017; IARC 2012; Servetas et al. 2016).

H. pylori infection is usually acquired in childhood and can cause inflammation or irritation of the lining (mucosa) of the stomach (chronic infection, or gastritis). This gastritis is associated with recruitment of various types of immune cells (e.g., neutrophils and lymphocytes). Progression to more serious stomach diseases, such as ulcers, MALT lymphoma, and non-cardia gastric cancer, occurs as the infected individual grows older, and it depends on factors specific to the infected individual and to the bacterium, as well as on the acidity of the stomach environment. Chronic inflammation of the stomach mucosa (chronic atrophic gastritis, occurring mainly in the corpus of the stomach) is associated with changes in the types of tissues and cells in the stomach (IARC 2012).

Most individuals infected with H. pylori do not develop symptoms; however, in some people, atrophic gastritis can progress to stomach ulcers or precancerous lesions (e.g., intestinal metaplasia and dysplasia), which can progress to stomach cancer (adenocarcinoma). Several studies provided evidence that progression of gastric lesions increased the risk of H. pylori-induced gastric cancer. A cohort study of middle-aged Japanese men found that the risk of H. pylori-induced gastric cancer relative to that in uninfected men increased with increasing severity of H. pylori lesions (i.e., from non-chronic atrophic gastritis to chronic atrophic gastritis to metaplastic gastritis (Ohata et al. 2004; Yoshida et al. 2014). A German cohort study found that having chronic atrophic gastritis was associated with a fivefold increase in the risk of non-cardia gastric cancer (Chen et al. 2016). In this study, serological biomarkers were used to assess the stages of gastritis.

In infected individuals with higher acid secretion, gastritis is more likely to develop in the lower part of the stomach (antrum-predominant gastritis) and can progress to ulcers in the small intestine (duodenal ulcers). Gastric MALT lymphoma can develop from gastritis in any part of the stomach (pangastritis) (Conteduca et al. 2013; IARC 2012; Ishaq and Nunn 2015; Testerman and Morris 2014).

H. pylori-induced chronic inflammation can lead to oxidative stress, aberrant expression of genes (e.g., suppression of the expression of some genes and enhancement of the expression of others, primarily via the process of aberrant DNA methylation), and disruption of enzymes involved in repairing DNA damage. This results in increased DNA damage in cells of the stomach lining (epithelial cells) and can result in mutation and genetic instability (Graham 2015; Maeda et al. 2017; Servetas et al. 2016). In addition, H. pylori either directly or indirectly (e.g., via inflammation) targets biological pathways involved in cell turnover, survival, and proliferation (e.g., by inhibiting tumor-suppressor genes). H. pylori also initiates changes in the characteristics of stomach epithelial cells (known as the “epithelial to mesenchymal transition”) that enable the cells to proliferate as cancer cells do (Servetas et al. 2016).

Some of these biological effects vary depending on virulence factors, the production of which can differ among H. pylori strains. For example, some H. pylori strains (such as CagA-positive strains) can induce a high degree of chronic inflammation (Figura et al. 2016). Moreover, studies in animals and cells have shown that CagA is an oncoprotein (i.e., when the gene is transferred into cells or animals, it causes gastric cells to proliferate and develop into tumors) (Wang et al. 2015). Virulence factors in H. pylori strains vary geographically, which may help to explain geographical patterns of stomach cancer risk (Wang et al. 2015; Yamaoka and Graham 2014). As discussed above, cancer risks are higher for CagA-positive H. pylori infection than for CagA-negative infection. A German cohort study (Chen et al. 2016) found that people with H. pylori CagA-positive infection who had markers in their blood for chronic atrophic gastritis had a much higher risk of developing non-cardia gastric cancer (hazard ratio [HR] = 32.4, 95% CI = 7.6 to 137.6) than did people without these two risk factors. These biological effects (chronic inflammation, changes in gene expression, mutations, genomic instability, and cellular proliferation) are associated with carcinogenesis.

### 2.4.4 NTP’s Listing Recommendation

Helicobacter pylori (chronic infection) is known to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in humans. This conclusion is based on epidemiological studies showing that H. pylori infection causes stomach cancer (especially non-cardia gastric cancer) and a specific type of lymphoma in the stomach (gastric MALT lymphoma).

H. pylori is estimated to cause 89% of non-cardia gastric cancer and 92% to 98% of all gastric MALT lymphoma cases. It is responsible for approximately 780,000 cancer cases (primarily gastric cancer) worldwide each year, accounting for 6.2% of all cancer cases (Plummer et al. 2015; Testerman and Morris 2014). Mechanistic and toxicological data indicate that chronic infection of the stomach with H. pylori is required for carcinogenicity, and they demonstrate the biological plausibility of its carcinogenicity. Studies in experimental animals indicate that H. pylori induces types of tumors similar to those found in humans: adenocarcinoma and lymphoma of the stomach.

## 2.5 Regulations

### 2.5.1 Department of Transportation (DOT)

Infectious substances are considered hazardous materials, and special requirements have been set for marking, labeling, and transporting these materials.

### 2.5.2 Food and Drug Administration (FDA, an Agency of Health and Human Services)

Helicobacter pylori is listed as a qualifying pathogen having the potential to pose a serious threat to public health under the Generating Antibiotic Incentives Now (GAIN) title of the Food and Drug Administration Safety and Innovation Act (FDASIA). GAIN is intended to encourage development of new antibacterial and antifungal drugs for the treatment of serious or life-threatening infections.

### 2.5.3 Occupational Safety and Health Administration (OSHA)

First-aid training program trainees must have adequate instruction in the value of universal precautions for minimizing exposure to blood and other potentially infectious material.