# 1. Objective and Methods

## 1.1 Objective

Helicobacter pylori is a gram-negative, multi-flagellated bacterium that colonizes the luminal mucosal surface of the body (corpus) and lower portion (antrum) of the stomach; if untreated, the infection usually lasts for the individual’s lifetime. Chronic infection can cause gastritis and peptic ulcers.

The objective of this monograph is to present NTP’s conclusions regarding the level of evidence for carcinogenicity from studies in humans and experimental animals and its Report on Carcinogens (RoC) listing recommendation. These conclusions were reached by applying the RoC listing criteria to the cancer assessment.

The rationale for selecting H. pylori for review for the RoC and the approach to preparing the monograph were outlined in the draft concept document, “Helicobacter pylori: Chronic Infection” (NTP 2016). The draft concept document was released for public comment and presented to the NTP Board of Scientific Counselors at its meeting on April 11, 2016, which provided opportunity for written and oral public comments. After the meeting, the concept document was finalized, and H. pylori was approved by the NTP Director as a candidate substance for review. The concept document is available on the RoC website (NTP 2016).

## 1.2 Monograph Development and Contents

In developing the monograph, NTP relied on the International Agency for Research on Cancer assessment (IARC 2012) and peer review of the cancer studies in humans and experimental animals and mechanistic and other relevant data. The rationale for relying primarily upon the IARC monograph is that the role of H. pylori as the major risk factor for stomach cancer is well established in the scientific community [see the concept document, NTP (2016)].

H. pylori infection is responsible for approximately 780,000 cancer cases annually worldwide (Plummer et al. 2015). The current question for the health community is not about causation, but whether H. pylori screening and eradication programs should be implemented and, if so, how these prevention strategies should be carried out. Therefore, this monograph also reports on the status of activities for preventing H. pylori-induced stomach cancer. Providing information on activities to reduce exposure is consistent with the spirit of the congressional mandate for the RoC (as the report is expected to discuss Federal agency regulations to limit exposure) and should facilitate hazard communication efforts when the RoC monograph is published.

The monograph consists of the following sections:

- Objective and methods (Section 1), including methods for conducting the cancer hazard evaluation (Section 1.3)
- Substance profile: Science supporting the listing recommendation (Section 2)
- Status and summary of cancer prevention strategies (Section 3)
- Appendices: Literature search strategies and a summary of human studies of H. pylori infection and pancreatic and colorectal cancer

The substance profile includes a description of the substance, discussion of exposure-related data, a summary of the scientific information considered key to its listing, and applicable current federal regulations and guidelines to limit exposure. If H. pylori is listed in the 15th RoC, then the substance profile (but not the other sections of the monograph) will become part of the RoC. The profile is written for a broad audience.

## 1.3 Methods for Conducting the Cancer Hazard Evaluation

As outlined in the concept document, NTP conducted several problem-formulating activities. These included searching the peer-reviewed literature (1) to determine the extent of U.S. exposure to H. pylori and (2) to identify any potential controversies concerning IARC’s assessment or any reports of cancer studies published since the IARC review whose findings were not consistent with findings from the earlier studies. Based on these literature searches, no information was identified that would argue against using the IARC assessment as the scientific basis for applying the RoC listing criteria and reaching a listing recommendation. NTP did not conduct its own systematic review of the primary cancer studies in humans and experimental animals.

The scientific information in the substance profile and cancer prevention strategies sections underwent scientific review and quality assurance review by a separate reviewer. The information in the profile was checked against the cited reference (e.g., IARC monograph, primary reference, review, or meta-analysis). Any discrepancies were resolved between the writer and the reviewer through discussion and reference to the original data source.

### 1.3.1 Selection of the Literature

NTP supplemented the IARC assessment and peer review of the cancer studies in humans and experimental animals and mechanistic studies (IARC 2012) with recent reviews or meta-analyses on cancer and mechanistic studies and exposure information. NTP also reviewed individual studies (cited in reviews, the IARC monograph, or other publications) when information in the IARC monograph was not clear or was related to a specific scientific issue.

Details on the literature search procedures and search terms are available in Appendix A.

### 1.3.2 Evaluation of Human Cancer Studies

NTP applied the RoC listing criteria (shown at the end of Section 1.3) to the body of literature to reach a decision on the level of evidence (sufficient, limited, or inadequate) for carcinogenicity based on cancer studies in humans. Human cancer studies on H. pylori infection were reported in the most recent IARC monograph on H. pylori (IARC 2012). NTP supplemented this information with a few more-recent studies that addressed key issues, such as information regarding chronic infection.

NTP focused on the two cancer outcomes for which IARC concluded there was sufficient evidence of carcinogenicity from studies in humans: stomach cancer and gastric mucosa-associated lymphoid tissue (MALT) lymphoma (IARC 2012), Tables 2.1 (https://monographs.iarc.fr/wp-content/uploads/2018/06/100B-10-Table2.1.pdf), 2.2 (https://monographs.iarc.fr/wp-content/uploads/2018/06/100B-10-Table2.2.pdf), 2.3 (https://monographs.iarc.fr/wp-content/uploads/2018/06/100B-10-Table2.3.pdf), 2.4 (https://monographs.iarc.fr/wp-content/uploads/2018/06/100B-10-Table2.4.pdf), 2.5 (https://monographs.iarc.fr/wp-content/uploads/2018/06/100B-10-Table2.5.pdf), 2.6 (https://monographs.iarc.fr/wp-content/uploads/2018/06/100B-10-Table2.6.pdf), and 2.7 (https://monographs.iarc.fr/wp-content/uploads/2018/06/100B-10-Table2.7.pdf)). Evidence was considered to be lacking for H. pylori as a cause of esophageal cancer (adenocarcinoma). In evaluating the human cancer data, NTP considered (1) IARC working-group comments on the strengths and limitations of the studies, (2) the consistency of a positive association across studies, (3) patterns such as exposure-response or latency relationships, (4) effect modifiers or co-factors, and (5) whether the association across studies could be explained by chance, bias, or confounding. The science supporting the NTP level-of-evidence conclusions is captured in the substance profile (Section 2).

With respect to other types of cancer, the IARC working group expressed concerns about the quality of the studies or the small numbers of studies available (IARC 2012). NTP also reviewed recent meta-analyses, systematic reviews, and other reviews evaluating the association of H. pylori infection with other types of cancer, primarily pancreatic and colorectal cancer. In general, primary studies on these two types of cancer were identified from the meta-analyses or cited references. Based on the review of recent studies and of the IARC monograph, NTP concluded that no formal cancer hazard evaluation of pancreatic or colorectal cancer was warranted. A short summary of the updated findings on pancreatic and colorectal cancer is provided in Appendix B.

### 1.3.3 Evaluation of Cancer Studies in Experimental Animals

NTP applied the RoC listing criteria to the body of literature to reach a decision on the level of evidence (sufficient or not sufficient) from cancer studies in experimental animals. NTP accepted IARC’s conclusions concerning the association between H. pylori infection and specific types of tumors (e.g., gastric adenocarcinoma and gastric lymphoma) in various animal models to determine whether the increases in tumors occurred at multiple tissue sites or in multiple species, or whether tumors occurred to an unusual degree with respect to incidence, site, type of tumor, or age at onset. In evaluating the data on cancer in experimental animals, NTP considered sources of heterogeneity across studies, such as differences in H. pylori strain, animal strain, or experimental methods, such as study duration.

### 1.3.4 Evaluation of Mechanistic and Other Relevant Data

The objective of the section on mechanistic and other relevant data is to provide a concise overview of the pathogenesis of H. pylori chronic infection and potential mechanisms of H. pylori carcinogenicity. As mentioned above, the substance profile is written for a broad audience, and its purpose is to provide an overview of the information that was key to the listing recommendation. Therefore, this section does not provide a detailed, comprehensive assessment of the mechanistic data or develop proposed modes of action. However, the section does evaluate whether the available mechanistic data provide biological plausibility for the findings observed in humans.

### 1.3.5 Overall Evaluation and Listing Recommendation

The evidence from the cancer studies in humans and experimental animals was integrated with the assessment of the mechanistic and other relevant data. The RoC listing criteria were then applied to the body of knowledge to reach a listing recommendation regarding chronic infection with H. pylori.

RoC Listing Criteria

##### Known to Be Human Carcinogen

There is sufficient evidence of carcinogenicity from studies in humans*, which indicates a causal relationship between exposure to the agent, substance, or mixture, and human cancer.

##### Reasonably Anticipated to Be Human Carcinogen

There is limited evidence of carcinogenicity from studies in humans*, which indicates that causal interpretation is credible, but that alternative explanations, such as chance, bias, or confounding factors, could not adequately be excluded, OR

there is sufficient evidence of carcinogenicity from studies in experimental animals, which indicates there is an increased incidence of malignant and/or a combination of malignant and benign tumors (1) in multiple species or at multiple tissue sites, or (2) by multiple routes of exposure, or (3) to an unusual degree with regard to incidence, site, or type of tumor, or age at onset, OR

there is less than sufficient evidence of carcinogenicity in humans or laboratory animals; however, the agent, substance, or mixture belongs to a well-defined, structurally related class of substances whose members are listed in a previous Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen, or there is convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans.

Conclusions regarding carcinogenicity in humans or experimental animals are based on scientific judgment, with consideration given to all relevant information. Relevant information includes, but is not limited to, dose response, route of exposure, chemical structure, metabolism, pharmacokinetics, sensitive sub-populations, genetic effects, or other data relating to mechanism of action or factors that may be unique to a given substance. For example, there may be substances for which there is evidence of carcinogenicity in laboratory animals, but there are compelling data indicating that the agent acts through mechanisms which do not operate in humans and would therefore not reasonably be anticipated to cause cancer in humans.

*This evidence can include traditional cancer epidemiology studies, data from clinical studies, and/or data derived from the study of tissues or cells from humans exposed to the substance in question that can be useful for evaluating whether a relevant cancer mechanism is operating in people.

## 1.4 Method for Developing the Section on Prevention of H. pylori-associated Cancer

The purpose of the section is to provide information and summarize studies and expert working group recommendations related to the prevention of H. pylori-associated gastric cancers. The IARC working group report, “Helicobacter pylori Eradication as a Strategy for Preventing Gastric Cancer,” served as the basis for Section 3 of the monograph (IARC 2014). The information was supplemented with new studies that evaluated the effectiveness of screening and eradication, cost-benefit analysis, and expert or government recommendations or guidelines. NTP did not make an assessment of the studies or provide its own recommendations or policies. The scientific information in the cancer prevention strategies sections underwent scientific review and quality assurance review by a separate reviewer, in a process similar to that described for the substance profile.