# Appendix B Summary of Human Studies of Pancreatic and Colorectal Cancer

As mentioned in the Objective and Methods, NTP also reviewed recent meta-analyses, systematic reviews, and other reviews evaluating the association of H. pylori infection and other types of cancer, primarily pancreatic and colorectal cancer. A short summary of the updated findings on pancreatic and colorectal cancer is provided below.

## B.1 Pancreatic Cancer

The 2009 IARC evaluation of H. pylori included four nested case-control studies (see IARC (2012), Table 2.21 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-10-Table2.21.pdf)) and one case-control study of pancreatic cancer (Raderer et al. 1998). Since that time, five case-control studies (Gawin et al. 2012; Risch et al. 2014; Risch et al. 2010; Schulte et al. 2015; Shimoyama et al. 2010), one nested case-control study (Huang et al. 2017), two cohort studies (Chen et al. 2016; Hsu et al. 2014), and an update of a nested case-control study [Yu et al. (2013), which updated Stolzenberg-Solomon et al. (2001)] were identified. In addition, several recent meta-analyses were identified, of which the analysis by Schulte et al. (2015), which included 11 studies, was considered to be the most informative. This analysis reported meta ORs of 1.13 (95% CI = 0.86 to 1.50; 11 studies) for H. pylori infection and pancreatic cancer, 0.78 (95% CI = 0.67 to 0.91; 6 studies) for cytotoxin-associated gene A- (CagA-) positive strains, and 1.30 (95% CI = 1.02 to 1.65; 4 studies) for CagA-negative strains. The meta-analysis did not include the recent large nested case-control study by Huang et al. (2017), which did not find an association with H. pylori infection, or sub-analyses for Cag-negative or -positive strains, nor the ESTHER cohort study, which found non-significant elevated risks for H. pylori infection with CagA-negative strains (Chen et al. 2016). NTP considered the database of studies inadequate to evaluate the association between H. pylori infection and pancreatic cancer and did not conduct a formal evaluation.

## B.2 Colorectal Cancer

The 2009 IARC working group evaluation of H. pylori included 12 case-control studies (IARC (2012), Table 2.19 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-10-Table2.19.pdf)) and two nested case-control studies of colorectal cancer (IARC (2012), Table 2.18 (https://monographs.iarc.fr/ENG/Monographs/vol100B/100B-10-Table2.18.pdf)). Since that time, several meta-analyses and at least ten studies on colorectal cancer have been published. Recent meta-analyses that were specific for colorectal cancer (i.e., did not include colon adenoma) reported modestly increased colorectal cancer risks (~20% to 40%) with H. pylori infection [e.g., Rokkas et al. (2013); Wang et al. (2014); Wu et al. (2013)]; however, heterogeneity was observed, and many studies included in the analyses were small, cross-sectional, hospital-based case-control studies, or did not adjust for potential confounding factors. The most informative studies were four large population-based case-control studies (Fernández de Larrea-Baz et al. 2017; Machida-Montani et al. 2007; Zhang et al. 2012; Zumkeller et al. 2007), three nested case-control studies (Blase et al. 2016; Epplein et al. 2013; Limburg et al. 2002), and a cohort study (Chen et al. 2016) that reported adjusted risk estimates. Findings among these studies were inconsistent. Two population-based case-control studies in Germany (Zhang et al. 2012; Zumkeller et al. 2007) found positive associations with H. pylori infection. In addition, two nested case-control studies, an analysis within the U.S. Southern Community Cohort Study (Epplein et al. 2013), and an analysis of elderly Caucasians in the CPS-II Nutrition Cohort (Blase et al. 2016) reported positive associations with some specific H. pylori antigens but not H. pylori infection in general. Few studies have looked at specific antigens, and the results were inconsistent across studies. The other informative studies did not find an association with H. pylori infection or specific antigens (Chen et al. 2016; Fernández de Larrea-Baz et al. 2017; Limburg et al. 2002; Machida-Montani et al. 2007). The evidence for an association between H. pylori infection and colon adenoma or polyps may be stronger, but adenoma is outside the scope of a cancer hazard evaluation. Based on this initial review, NTP did not conduct a formal evaluation of colorectal cancer.