# Appendix A Literature Search Strategy

The objective of the literature-search approach was to identify published literature relevant for evaluating the potential carcinogenicity of the Helicobacter pylori (H. pylori) bacterium. As discussed in the Helicobacter pylori Concept Document (NTP 2016), this monograph relies on the IARC (2012) monograph and key studies published since the monograph. Two literature searches were conducted: (1) to identify key reviews or meta-analyses for updating exposure and mechanistic data and for determining whether a formal review of other cancer sites was merited and (2) to identify intervention and prevention studies published since the 2014 publication of the IARC working group report on H. pylori eradication.

## A.1 Identification of Intervention Studies

### A.1.1 General Approach

Database searching encompasses selecting databases and search terms, as well as conducting the searches. Searches of several citation databases generally use search terms for the individual topic of interest, along with search terms for cancer and/or specific topics, including epidemiological and mechanistic studies. A critical step in the process involves consultation with an information specialist to develop relevant search terms, which are used to search bibliographic databases. The IARC working group report on H. pylori eradication was published in 2014, so PubMed, Web of Science, and Scopus were searched for new information about H. pylori from 2013 through 2017. Table A-1 highlights the general concepts searched, with selected example terms.

Table A-1 Major Topics Searched

Topics | Example Terms
H. pylori | H-pylori, Helicobacter pylori, Helicobacter-pylori
Intervention/prevention | Controlled before-after studies, Interrupted time series analysis, Early medical intervention, Treatment, Intervention, Therapy, Prevention
Study type and topics | Meta-analysis, Clinical trial, Public health surveillance, Medical economics, Markov chains, Statistical models, Health care costs, Cost-benefit analysis, Review, Treatment outcome
Cancer | Neoplasms, Carcinogenicity tests, Carcinogens

The large and complex body of literature for H. pylori was searched through the use of narrowing terms for the relevant major topics within the bibliographic databases. The results were then processed in EndNote to remove duplicates, before being transferred to Health Assessment Workspace Collaborative (HAWC), a computational content management system, for screening.

The bibliographic database search results (1,198 references) were processed in EndNote and then imported into HAWC for first- and second-tier screening. Relevant studies found through the citations in review articles and other secondary searches were also included. Tagging in HAWC categorized the useful articles into categories such as Health Assessment (66 references), Antibiotic intervention (31 references), Other Intervention (19 references), and so on.

### A.1.2 Search Strings for H. pylori Searches

Each search detailed below was limited to publication years from 2013 to 2017 and were combined with the RoC Cancer Filter (https://ntp.niehs.nih.gov/ntp/roc/handbook/rochandbookappendix_508.pdf).

Table A-2 The Full Search Strings for H. pylori Searches

Database | Search Terms
PubMed | ((“Meta-Analysis”[pt] OR meta-analysis[tiab] OR Meta-Analyses[tiab] OR MetaAnalysis[tiab] OR metaanalyses[tiab]) OR (“Clinical Trial”[pt] OR Clinical-Trial*[tiab]) OR (“Public Health Surveillance”[mh] OR “Economics, Medical”[mh]) OR (“Markov Chains”[Mh] AND “Models, Statistical”[Mh] OR Markov-chain*[tiab]) OR (“Health Care Costs”[mh] OR “Cost-Benefit Analysis”[mh] OR cost-benefit[tiab]) OR “Review”[pt] OR “Treatment Outcome”[mh])) AND ((“Controlled Before-After Studies”[Mh] OR “Interrupted Time Series Analysis”[Mh] OR “Early Medical Intervention”[Mh] OR Treatment*[tiab] OR intervention*[tiab] OR therapies[tiab] OR Therapy[tiab] OR prevent*[tiab])) AND (H-pylori[tiab] OR “Helicobacter pylori”[mh] OR Helicobacter-pylori[tiab])
Web of Science | (TS=(“Meta-Analysis” OR “Meta-Analyses” OR “Metaanalysis” OR “metaanalyses” OR “Review” OR “Clinical Trial*” OR “Public Health Surveillance” OR “Medical Economics” OR “Markov Chain*” OR “Health Care Costs” OR “Cost-Benefit Analysis” OR cost-benefit OR “Review” OR “Treatment Outcome”)) AND (TS=(“Controlled Before-After Studies” OR “Interrupted Time Series Analysis” OR “Early Medical Intervention” OR Treatment* OR intervention* OR therapies OR Therapy OR prevent*)) AND (TS=(H-pylori OR “Helicobacter pylori”))
Scopus | (TITLE-ABS-KEY (“Meta-Analysis” OR “Meta-Analyses” OR “Metaanalysis” OR “metaanalyses” OR “Review” OR “Clinical Trial*” OR “Public Health Surveillance” OR “Medical Economics” OR “Markov Chain*” OR “Health Care Costs” OR “Cost-Benefit Analysis” OR cost-benefit OR “Review” OR “Treatment Outcome”)) AND (TITLE-ABS-KEY (“Controlled Before-After Studies” OR “Interrupted Time Series Analysis” OR “Early Medical Intervention” OR Treatment* OR intervention* OR therapies OR Therapy OR prevent*)) AND (TITLE-ABS-KEY (H-pylori OR “Helicobacter pylori”))

## A.2 Identification of Cancer and Exposure Studies, Reviews, and Meta-analyses

Literature on cancer and exposure studies, reviews, and meta-analyses related to H. pylori infection were identified through the use of narrowing terms for the relevant major topics within PubMed, and the resulting citations were saved directly into HAWC. HAWC was used to screen results and eliminate out-of-scope or duplicate references.

1. Prevalence searches in PubMed combined the MeSH term for H. pylori with the MeSH term for prevalence, limited to reviews published in the past 5 years, and 69 references were added to HAWC for evaluation.
2. Diagnosis searches used the H. pylori MeSH term and the diagnosis MeSH term, limited to review articles published since 01/01/2017, and 19 references were added to HAWC.
3. Finally, 368 recent reviews and meta-analyses for H. pylori were identified and added to HAWC for evaluation.

## A.3 Updating the Literature Search

The literature searches were last updated in PubMed, Scopus, and Web of Science on January 5, 2018. No additional publications were recommended by the peer reviewers.