# 8 Evidence Integration and Listing Recommendation

The purpose of this monograph is to assess the data on the carcinogenicity of antimony(III) trioxide. This section integrates the assessments of the studies on cancer in animals (Section 8.1), mechanistic and other relevant data (Section 8.2), and studies on cancer in humans (Section 8.3).

## 8.1 Evidence of Carcinogenicity from Studies in Experimental Animals

There is sufficient evidence of the carcinogenicity of antimony(III) trioxide from studies in experimental animals.

The conclusion that antimony(III) trioxide is carcinogenic is based on increased incidences of malignant tumors and increased combined incidences of benign and malignant tumors at several tissue sites in two rodent species exposed to antimony(III) trioxide by inhalation. Increased incidences were observed for lung tumors in rats and mice of both sexes, adrenal gland tumors in female rats, skin tumors in male mice, and lymphoma in female mice (see Section 5, Table 5-1 and Table 5-4). In a 2-year study (NTP 2017a), the increased incidences of alveolar/bronchiolar carcinoma and the increased combined incidences of alveolar/bronchiolar adenoma and carcinoma both occurred at exposure levels below the concentration resulting in potential lung overload.

## 8.2 Summary of Mechanistic Data

The data from mechanistic studies provide plausible support for carcinogenic activity. Because antimony(III) trioxide may exert its effects through released trivalent antimony ions, effects observed with other trivalent antimony compounds are potentially relevant.

Although electrophilicity of antimony(III) trioxide has not been reported, antimony compounds are electrophilic and might interact directly with nucleic acids and proteins. Trivalent antimony is highly reactive with sulfhydryl groups and, in particular, vicinal thiol groups. Proteins containing vicinal thiol groups include GSH and enzymes that bind to DNA.

Antimony(III) trioxide and other antimony compounds increase oxidative stress and cause oxidative damage. Antimony(III) trioxide causes DNA damage and micronucleus formation in rodents after in vivo exposure, and causes DNA damage, chromosomal aberrations, and sister chromatid exchange after in vitro exposure, although antimony(III) trioxide is generally not mutagenic.

Although antimony(III) trioxide did not affect unscheduled DNA synthesis (an indirect and not sensitive indicator of DNA repair), two other antimony(III) compounds decreased DNA repair capacity in human cells in vitro, and the effect was due at least in part to displacement of the zinc(II) in the zinc fingers of a DNA repair enzyme.

Antimony(III) potassium tartrate prevents cell differentiation and increases colony formation of human keratinocytes in vitro, at least in part by stabilizing the level of EGFR and elevating the level of β-catenin, a proto-oncogene.

Consistent with antimony’s known high affinity to zinc finger domains of the proteins, several antimony(III) compounds showed antagonist effects on nuclear receptors in high-throughput screening assays, but whether this occurs in vivo has not been confirmed. Although antimony exposure has been associated with global DNA methylation changes in one human study, the role of epigenetic changes in its carcinogenicity is unclear. The immune effects of antimony(III) compounds are unclear.

## 8.3 Evidence of Carcinogenicity from Studies in Humans

The data from epidemiological studies are inadequate to evaluate the relationship between human cancer and exposure specifically to antimony(III) trioxide or other antimony compounds.

Elevated mortality was reported in three cohort studies of antimony-exposed workers in the United States (Jones et al. 2007; Schnorr et al. 1995) and the United Kingdom (Jones 1994). In addition, an increased risk of stomach cancer was found in the U.S. antimony smelter cohort study (Schnorr et al. 1995) and a Swedish case-control study of glass workers (Wingren and Axelson 1993), but not in the U.K. antimony smelter cohort study (Jones 1994). However, few studies evaluated each type of cancer, and the results may have been affected by nondifferential exposure misclassification and confounding bias due to co-exposure to other metals.

## 8.4 Listing Recommendation

This listing recommendation is based on applying the RoC listing criteria to the body of scientific evidence provided in this monograph.

Antimony(III) trioxide increased the incidences of malignant tumors or the combined malignant and benign tumors at two tissue sites in rats (lung and adrenal gland) and three sites in mice (lung, skin, and lymphoid system).

Biological effects associated with carcinogenicity include increases in oxidative stress and oxidative damage, impairment of DNA damage repair, and possibly inhibition of cell differentiation.

Antimony(III) trioxide is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals and supporting data from mechanistic studies.