# 7 Other Relevant Data

This section reviews (1) carcinogenic studies on other antimony compounds and (2) conclusions regarding non-cancer health outcomes.

## 7.1 Carcinogenicity Studies of Other Antimony Compounds

Studies of exposure to antimony(III) potassium tartrate in the drinking water in Long-Evans rats (Schroeder et al. 1970) or Swiss CD-1 mice (one study reported in Kanisawa and Schroeder (1969) and Schroeder et al. (1968)) showed no increases in tumors (see Appendix F.1 for details on the findings). However, limitations of the study design and reporting leave the question of the carcinogenicity of antimony(III) potassium tartrate unanswered. Limitations in the rat study included the death of many rats from pneumonia and performance of only a gross necropsy (no histopathological examination). In the mouse study, the limitations included testing of only one exposure concentration, which might not have been the maximally tolerated dose; histological evaluation of only gross lesions; and reporting of tumor incidences only for both sexes combined. Antimony(III) potassium tartrate administered orally has relatively low bioavailability (NTP 1992). It is not known whether exposure to antimony(III) potassium tartrate via a more bioavailable route would cause tumors. No carcinogenicity studies of other antimony compounds were identified.

## 7.2 Noncancer Health Outcomes

Non-carcinogenic health effects resulting from exposure to antimony are described elsewhere. ATSDR (2017) conducted a systematic review of non-cancer effects in workers and animals exposed to antimony (elemental antimony, antimony ore, and various antimony compounds) and concluded that antimony is presumed to cause respiratory health effects (e.g., pneumoconiosis, coughing, and laryngitis) in workers following inhalation exposure and gastrointestinal tract irritation following oral exposure and injections. Suspected human health effects of antimony, based primarily on evidence from animal studies, are cardiovascular (myocardial and electrocardiogram alterations), metabolic (decreased serum glucose levels), and developmental (decreased postnatal growth and birth weight and other effects). While NTP RoC did not investigate the biological alterations leading to these non-cancer health effects or how they might be associated with carcinogenicity, observed respiratory health effects were seen in the lung, a cancer site in experimental animals exposed to antimony trioxide via inhalation.