# 6 Mechanistic Data

Section 6 provides mechanistic data related to understanding the carcinogenicity of antimony trioxide observed in experimental animals (Section 5). Tumor sites observed in animal include lung tumors in rats and mice, adrenal gland tumors in rats, and skin and lymphoma in mice.

Most of the section discusses mechanistic data on antimony(III) trioxide and antimony(III) trichloride, which is similar to antimony(III) trioxide, and is generally organized according to the 10 key characteristics of human carcinogens (Smith et al. 2016) (see Characteristics in Table 6-1), with minor exceptions (see next paragraph). The order of the presentation is by both possible chronological sequence of events (e.g., being electrophilic leads to binding with GSH, and the efflux of antimony GSH complex in turn causes oxidative stress) and the weight of evidence (evidence from antimony(III) trioxide carries more weight than evidence from other antimony compounds). No metabolic activation is needed for the antimony effects seen.

Table 6-1 Ten Characteristics of Carcinogens (Smith et al. 2016) and Organization of Section 6

Number | Characteristic | Section Number | Section Header
1 | Act as an electrophile either directly or after metabolic activation | 6.1 | Electrophilic properties
2 | Be genotoxic | 6.3 | Genotoxicity
3 | Alter DNA repair or cause genomic instability | 6.4 | Inhibition of DNA repair
4 | Induce epigenetic alterations | 6.7 | Epigenetic alterations
5 | Induce oxidative stress | 6.2 | Oxidative stress
6 | Induce chronic inflammation | 6.6 | Immunomodulation and inflammation
7 | Be immunosuppressive | – | (combined with inflammation)
8 | Modulate receptor-mediated effects | – | (combined with cell proliferation)
9 | Cause immortalization | – | (no information)
10 | Alter cell proliferation, cell death, or nutrient supply | 6.5 | Alteration of cell proliferation, cell death, and receptor-mediated effects (no information on altered nutrient supply)

The section (see Section number and Section header in Table 6-1) starts with electrophilic properties (Section 6.1), oxidative stress (Section 6.2), genotoxicity (Section 6.3), and inhibition of DNA repair (Section 6.4). Due to limited information available, receptor-mediated effects are integrated into the section on cell proliferation and cell death (i.e., alteration of cell proliferation, cell death, and receptor-mediated effects (Section 6.5). Little information is available for antimony immunomodulation and inflammation (Section 6.6) and epigenetic alterations (Section 6.7) contributing to antimony trioxide carcinogenicity, and therefore are presented last. Insufficient studies are available on alterations in cell nutrient supply and immortalization and these topics are not discussed. The relative abundance of the data in each section could be a reflection of available studies (e.g., genotoxicity has been studied much longer than epigenetic changes), rather than the nature of the effects.

## 6.1 Electrophilic Properties

Antimony compounds are electrophilic and might interact directly with nucleic acids (DNA and RNA) and proteins. Antimony, especially in its trivalent form, is highly reactive with sulfhydryl groups and, in particular, vicinal thiol groups (reviewed by Wysocki and Tamas (2010)). Thiol reactivity may directly affect toxicity by disrupting protein structure, function, and stability.

While direct effects of antimony(III) trioxide electrophilicity were not found, antimony(III) potassium tartrate directly inhibits glutathione (GSH) reductase (Moreira et al. 2017; Wyllie and Fairlamb 2006) and glutathione S-transferase (GST) in red blood cells (Poon and Chu 2000) (see Section 6.2 for additional details). Antimony(III) potassium tartrate also reduced protein thiols by 15% to 40% in neonatal cardiac myocytes (Tirmenstein et al. (1997) in Section 6.2). Reaction of antimony(III) with thiols can also target zinc finger domains of DNA-binding proteins and affect their functions, as seen in antimony(III) trichloride displacement of zinc in a DNA repair enzyme (Grosskopf et al. 2010) (see Section 6.4 for additional details). In the high-throughput screening using cultured cells, four antimony compounds, not including antimony(III) trioxide, were screened in various Tox21 assays (see Appendix E.1). They showed mostly antagonistic effects to nuclear receptors, possibly because of displacement of Zn(II) in the zinc finger structures of these receptors by antimony(III) ions.

## 6.2 Oxidative Stress

Cellular redox imbalance leads to excess accumulation of reactive oxygen species (ROS) and reactive nitrogen species, both of which can cause oxidative stress. Oxidative stress can cause cell damage, affect normal cell processes, and contribute to carcinogenicity (reviewed by Jones (2008); Kim et al. (2015); Smith et al. (2016)). Many studies show that trivalent antimony compounds increase oxidative stress in vivo and in vitro.

Although no studies of in vivo oxidative damage by antimony(III) trioxide were found, an in vivo effect of an antimony(V) compound has been reported. Exposure of mice to meglumine antimoniate(V) caused oxidative damage in the forms of protein carbonylation, lipid peroxidation (Bento et al. 2013), and DNA damage (Cantanhêde et al. 2015; Moreira et al. 2017). Organ-specific changes in catalase and superoxide dismutase activities support a role for ROS in protein and lipid damage (Bento et al. 2013; Moreira et al. 2017).

In vitro studies showed that antimony(III) compounds can react with thiol groups on proteins and peptides (e.g., the reduced form of GSH) (see Section 6.1) and consequently inhibit cellular antioxidant defenses. Exposure to antimony(III) trioxide (Mann et al. 2006) and other antimony(III) compounds (antimony trichloride (Hashemzaei et al. 2015) and antimony potassium tartrate (Poon and Chu 2000; Sudhandiran and Shaha 2003; Tirmenstein et al. 1997; Tirmenstein et al. 1995; Wyllie and Fairlamb 2006) led to an increase in ROS, disruption of mitochondrial membrane potential, or disruption of cellular redox metabolism (through GSH depletion or disruption of GSH production or utilization). The depletion of GSH results in part from the cell’s expulsion of trivalent antimony by binding antimony to GSH or co-transporting antimony and GSH out of the cell (Figure 6-1, #1). Antimony(III) potassium tartrate, but not sodium stibogluconate (which contains pentavalent antimony) inhibits GST activity (Poon and Chu 2000) (Figure 6-1, #3). Also inhibited by antimony are glutathione reductase, by antimony(III) potassium tartrate (Wyllie and Fairlamb 2006), and glutathione peroxidase, by meglumine antimoniate(V) (Moreira et al. 2017) (Figure 6-1, #4, #5).

Figure 6-1

Antimony Increases Oxidative Stress

The increase in oxidative stress is the overall result of individual effects: (#1) a decrease in the reduced form of glutathione (GSH), (#2) an increase in mitochondrial damage, including decreased mitochondrial membrane potential (MMP) and a consequent increase in ROS, (#3) reduced GST activity, and (#4) inhibition of the activities of GST and (#5) glutathione peroxidase and a consequent imbalance of GSH and its oxidized form (GSSG). Despite protective effects triggered by antimony, such as increased expression and nuclear translocation of nuclear factor (erythroid-derived 2)-like 2 (i.e., Nrf2) caused by antimony(III) trioxide (#6), the overall effect is increased oxidative stress and oxidative damage. Light gray arrows and text indicate effects seen with Sb(V) compounds but not yet studied with Sb(III) compounds.

Studies using antioxidants and inhibitors of various enzymes in the redox process showed that the effects of exposure to antimony(III) trioxide (Lösler et al. 2009; Mann et al. 2006), antimony(III) trichloride (Hashemzaei et al. 2015), and antimony(III) potassium tartrate (Lecureur et al. 2002) are modulated by oxidative stress and/or disruption of antioxidant systems (see Appendix E.2). For example, antimony(III) trioxide-induced apoptosis was further increased by depletion of GSH or inhibition of enzymes (γ-glutamylcysteine synthetase, glutathione peroxidase, or catalase) (Lösler et al. 2009).

Mitochondria can be affected by ROS and can contribute to increased ROS. Antimony(III) trioxide (Lösler et al. 2009), antimony(III) trichloride (Hashemzaei et al. 2015), and antimony(III) potassium tartrate (Lecureur et al. 2002) disrupted mitochondrial membrane potential (Blond and Whittam 1965) (Figure 6-1, #2) and induced ROS. Mitochondria, in turn, are a source of antimony(III) trichloride-induced oxidative stress. When primary rat hepatocytes were exposed to both antimony(III) trichloride and a mitochondrial protective agent, the ROS production was less than with exposure to antimony(III) trichloride alone (Hashemzaei et al. 2015). Exposure of cells to both antimony(III) trichloride and ROS scavengers prevented the antimony(III) trichloride-induced decrease in mitochondrial membrane potential.

## 6.3 Genotoxicity

This section summarizes the results of in vitro, in vivo, and human genotoxicity studies of antimony compounds. The focus is on antimony(III) trioxide, followed by antimony(III) trichloride, and findings from other antimony(III) compounds.

As summarized in Table 6-2, (1) antimony(III) trioxide and other antimony(III) compounds are not mutagenic in bacterial or mammalian cells, (2) antimony(III) trioxide can cause DNA damage in mouse lung in vivo after long-term inhalation exposure, and (3) antimony(III) trioxide can cause chromosomal aberrations in vitro, micronucleus formation in vivo, and SCE in vitro.

Table 6-2 Summary of Genotoxicity Data for Antimony(III) Trioxide and Antimony(III) Trichloride

Endpoint (Test System) | Antimony(III) Trioxide | | Antimony(III) Trichloride
Endpoint (Test System) | In Vitro | In Vivo | In Vitro | In Vivo
Mutation
Any mutation (prokaryotes) | Neg | – | Neg | –
Any mutation (eukaryotes) | Neg | * | – | –
DNA Damage
Any DNA damage (prokaryotes) | Pos | Pos | Pos | –
Any DNA damage (eukaryotes) | Pos | Pos | Pos | –
DNA-protein crosslinks | – | – | Neg | –
Chromosomal damage/cytogenetic effects
Chromosomal aberrations | Pos | Neg^a^ | – | ^b^
Micronucleus induction | – | Pos | Pos | Pos
Sister chromatid exchange | Pos | – | Pos | –

Results: Pos = positive, Neg = negative. – = not reported.

* Mutations were detected in antimony(III) trioxide-induced lung tumors (NTP 2017a).

^a^ Negative in rats; uncertain in mice due to severe study limitations.

^b^ Uncertain because only available study has severe study limitations.

Studies with severe limitations are not used for the assessment or discussed in the text, but study details and limitations are summarized in the tables in Appendix E.3 along with studies discussed in the text. This section is organized by genotoxic end point, including mutations, and damage to DNA, chromatids, and chromosomes. Within each end point, the results are generally presented in the order of human studies, in vivo animal studies, in vitro mammalian cell studies, and in vitro bacterial cell studies.

### 6.3.1 Mutagenicity: Base Substitution and Frame Shift

Detailed results of the mutagenicity studies regarding base change and fame shift are shown in Appendix E.3, Table E-2.

No human cell study was found. In mouse lymphoma L5178Y TK^+/−^ cells in vitro antimony(III) trioxide did not increase mutations with or without liver S9 metabolic enzymes and cofactors (Elliott et al. 1998).

In bacterial cells (Salmonella typhimurium and Escherichia coli), antimony(III) trioxide (Elliott et al. 1998; Kanematsu et al. 1980; Kuroda et al. 1991) and antimony(III) trichloride (Kanematsu et al. 1980; Kuroda et al. 1991) were not mutagenic in tests conducted with or without S9 metabolic activation in multiple strains that tested both base pair substitutions and frameshift mutations. Overall, the data suggest that antimony(III) compounds are not mutagenic in bacterial assays.

### 6.3.2 DNA Damage

Detailed results of DNA damage studies are shown in Appendix E.3, Table E-3. Antimony(III) trioxide exposure was associated with DNA damage in mice and in cultured cells. No study specifically measuring DNA adduct was found.

Although two human studies (Cavallo et al. 2002; El Shanawany et al. 2017) reported an association between increased DNA damage and occupational antimony(III) trioxide exposure, the evidence is inconclusive, because of potential confounding from occupational co-exposures, lack of correlation of urine antimony levels with measured DNA damage, extremely high background levels of DNA damage in one study (El Shanawany et al. 2017), and other limitations.

In animal studies, after 12-month inhalation exposure to antimony(III) trioxide, B6C3F1/N mice of both sexes had significantly increased DNA damage in lung (at 3 mg/m^3^ or higher in females and 30 mg/m^3^ in males), but not in blood leukocyte samples at concentrations of up to 30 mg/m^3^, as measured by the comet assay (NTP 2017a). Wistar Han rats of both sexes with 12-month exposure to antimony(III) trioxide at up to 30 mg/m^3^ did not show increased DNA damage in the lung or blood leukocytes (NTP 2017a). Oral administration of antimony(III) trioxide to rats did not cause unscheduled DNA synthesis, an indicator of repair of DNA damage, which is less sensitive than the direct measurement of DNA damage (Elliott et al. 1998).

In vitro studies of human whole blood and peripheral blood lymphocytes (Schaumlöffel and Gebel 1998) and V79 Chinese hamster cells (Gebel et al. 1998) exposed to antimony(III) trichloride showed increased DNA damage (single-strand breaks). DNA damage was detected below cytotoxic concentrations and did not involve DNA-protein crosslinks.

In prokaryotes, evidence for DNA damage has been reported from experiments with sensitive detection capacity. In modified rec assay protocols that increased the sensitivity of the Bacillus subtilis rec assay 20- to 50-fold (Hirano et al. 1982; Kada 1976), antimony(III) trioxide (Kanematsu et al. 1980; Kuroda et al. 1991) and antimony(III) trichloride (Kanematsu et al. 1980; Kuroda et al. 1991) both gave positive results. In the very sensitive plasmid pBR322 DNA-nicking assay, trimethylstibine (Sb(CH_3_)_3_) was genotoxic, but antimony(III) potassium tartrate was not (Andrewes et al. 2004). In contrast, in the less sensitive assays, antimony(III) trichloride did not induce SOS DNA repair genes in E. coli (Lantzsch and Gebel 1997) or S. typhimurium (Yamamoto et al. 2002). In the traditional B. subtilis rec assay, antimony(III) trichloride did not inhibit the growth in the repair-deficient bacteria (Nishioka 1975).

### 6.3.3 Chromosomal Aberrations, Micronucleus, and Sister Chromatid Exchange

Detailed results of chromosomal aberrations, micronucleus, and sister chromatid exchange (SCE) studies are shown in Appendix E.3, Table E-4.

Data in humans are scarce and have many limitations. Occupational inhalation exposure to antimony(III) trioxide did not increase micronucleus formation or SCE in peripheral blood lymphocytes in workers in one study; however, there were few subjects and workers were exposed to relatively low antimony levels (Cavallo et al. 2002).

In animal studies, chromosome aberrations in bone marrow were not increased by oral exposure to antimony(III) trioxide in rats for 3 weeks, even at a dose that resulted in decreased body weight (Kirkland et al. 2007). Because of the many limitations of the studies in mice (Gurnani et al. 1992a; 1992b), including unknown test substance purity, lack of positive controls, and mortality at the high dose, it is uncertain whether oral exposure to antimony(III) trioxide (Gurnani et al. 1992a) or antimony(III) trichloride (Gurnani et al. 1992b) induces chromosomal aberrations in mice. Antimony potassium tartrate (described as potassium antimonyl tartrate in the study) administered by intraperitoneal (i.p.) injections increased chromosomal aberrations (excluding gaps and including gaps) in the bone marrow of rats (El Nahas et al. 1982).

In vitro exposure of human leucocytes to antimony(III) trioxide led to increased chromosomal aberrant cells (excluding gaps) in both the presence and absence of S9 mixture (Elliott et al. 1998). Similarly, in vitro exposure to antimony(IIII) sodium tartrate increased chromatid breaks in human leucocytes (Paton and Allison 1972).

Antimony(III) trioxide increased micronuclei in mature erythrocytes (normochromatic erythrocytes) in mice, but not in rats, after 12 months of inhalation exposure; the increase in mice showed a significant dose-related trend and was significant at the highest dose (30 mg/m^3^) (NTP 2017a). Micronucleus frequencies in polychromatic erythrocytes were not increased in mice or rats after 12-month inhalation exposure to antimony(III) trioxide (NTP 2017a). Because approximately 1 million erythrocytes per animal were scored by flow cytometry for detection of micronuclei, the method is highly sensitive and able to detect small increases (NTP 2017a). In studies in which 2,000 polychromatic erythrocytes per rat were scored for micronuclei (the current recommendation is to score 4,000 immature erythrocytes per animal, (OECD 2016), antimony(III) trioxide did not increase micronuclei in erythrocytes in the bone marrow of mice 24 or 48 hours after a single oral gavage dose of 5,000 mg/kg of body weight (b.w.) or after 8, 15, or 22 days of daily dosing (at up to 1,000 mg/kg b.w.) (Elliott et al. 1998) or in rats after 21 days of daily oral dosing (at up to 1,000 mg/kg b.w. per day) (Kirkland et al. 2007).

In vitro exposure to antimony(III) trioxide increased micronuclei in Chinese hamster V79 ells (Gebel et al. 1998). Following in vitro exposure to antimony(III) trichloride, micronuclei were seen in human peripheral blood lymphocytes (Schaumlöffel and Gebel 1998), V79 Chinese hamster cells (Gebel 1998; Gebel et al. 1998), BES-6 human bronchial epithelial cells, human fibroblasts, and Chinese hamster ovary (CHO)-K1 cells (Huang et al. 1998). Because co-incubation with either superoxide dismutase or catalase did not affect the number of micronuclei detected in human lymphocytes, superoxide or peroxide oxygen species might not have a prominent role in promoting chromosomal damage (Schaumlöffel and Gebel 1998).

SCEs were increased by both antimony(III) trioxide and antimony(III) trichloride in human lymphocytes (Gebel et al. 1997) and Chinese hamster V79 cells (Kuroda et al. 1991).

Studies showed that antimony(III) trioxide and other antimony(III) compounds increased chromosomal aberrations, micronuclei, and sister chromatid exchange. Chromosomal aberrations included chromosome damage (excluding gaps) induced by antimony(III) trioxide by in vitro exposure of human cells (Elliott et al. 1998) and chromatid breaks induced by antimony(IIII) sodium tartrate by in vitro exposure of human cells (Paton and Allison 1972). Micronuclei were increased by antimony(III) trioxide in vivo and antimony(III) trichloride in vitro exposures. SCEs were increased by antimony(III) trioxide and antimony(III) trichloride in human cells (Gebel et al. 1997) and animal cells (Kuroda et al. 1991).

## 6.4 Inhibition of DNA Repair

Although effects of antimony(III) trioxide on DNA repair was only investigated indirectly in an unscheduled DNA synthesis study (Elliott et al. 1998), those of antimony(III) trichloride and antimony(III) potassium tartrate have in assays directly measure DNA damage repair and enzymes. As summarized in Table 6-3, these studies suggest that antimony(III) exposure leads to alterations in the abundance, phosphorylation, or localization of various proteins that regulate or mediate NER, NHEJ, and homologous recombination pathways. Whether antimony affects other repair pathways, including base-excision repair or mismatch repair, has not been investigated.

Table 6-3 DNA Repair Pathways and Molecules Altered by Exposure to Antimony(III) Compounds

DNA Repair Pathway(s) | Effects on DNA Repair | Molecules Affected | Reference
Antimony(III) trichloride
NER | Defect in lesion-specific repair of UVC-induced CPDs in A549 cells (no effect on repair of 6-4PP or BPDE-DNA adducts) | Decreased transcript and protein levels of XPE | Grosskopf et al. (2010)
NER | Defect in lesion-specific repair of UVC-induced CPDs in A549 cells (no effect on repair of 6-4PP or BPDE-DNA adducts) | Release of zinc from zinc finger domain of XPA | Grosskopf et al. (2010)
NHEJ and homologous recombination | Inhibition of repair of γ-irradiation-induced DSBs in HeLa cells | Diminished phosphorylation (i.e., activation) and recruitment of BRCA1 to DSB Antimony(III) trioxide itself had no impact on CHK1 or CHK2 phosphorylation, but it diminished γ-irradiation-induced phosphorylation of CHK1, but not CHK2 | Koch et al. (2017)
NHEJ and homologous recombination | Inhibition of repair of γ-irradiation-induced DSBs in HeLa cells | Prolonged presence of phosphorylated ATM foci at DSB, but ATM activity did not appear to be impaired | Koch et al. (2017)
homologous recombination | Inhibition of repair of γ-irradiation-induced DSBs in HeLa cells | Diminished association of the homologous recombination-specific marker RAD51 at DSB | Koch et al. (2017)
Antimony(III) potassium tartrate
NHEJ and homologous recombination | Inhibition of repair of γ-irradiation-induced DSBs in CHO-K1 cells | Not reported | Takahashi et al. (2002)

BPDE-DNA adducts = DNA adducts induced by (+)-anti-benzo[a]pyrene diol epoxide; BRCA1 = breast cancer type 1 susceptibility protein; CHK1 = checkpoint kinase 1 (protein); CHK2 = checkpoint kinase 2 (protein); ; RAD51 = DNA repair protein RAD51 (i.e., RAD51 recombinase).

Antimony(III) trioxide did not increase unscheduled DNA synthesis (an indicator of DNA repair) in the liver cells of rats received up to 5,000 mg/kg b.w. antimony(III) trioxide via a single oral gavage (Elliott et al. 1998). Because this assay is not very sensitive, the result does not conclusively rule out the possibility that antimony(III) trioxide might affects DNA damage repair.

Antimony(III) trichloride decreased the repair of cyclobutane pyrimidine dimers (CPDs) induced by ultraviolet C (UVC), but not the repair of (6-4) photoproducts (6-4 PP) induced by UVC or DNA adducts induced by benzo[a]pyrene diol epoxide (BPDE), in human lung carcinoma A549 cells (Grosskopf et al. 2010). Proteins in the nucleotide excision repair (NER) pathway were affected differently. Antimony(III) trichloride decreased transcript and protein levels of xeroderma pigmentosum complementation group E (XPE) protein, but it also released zinc from the zinc finger domain of xeroderma pigmentosum complementation group A (XPA) protein and consequently interfered with XPA function, without affecting XPA protein accumulation (Grosskopf et al. 2010). The lesion-specific effect of antimony(III) trichloride can be explained by the need for different enzymes to repair a particular lesion. The repair of the subtler helix disruption associated with CPDs requires XPE and XPA (which coordinates interaction with other NER complex proteins to repair CPDs, but not 6-4 PP), while the repair of the bulkier 6-4 PP is faster and may not require the activity of XPE (Grosskopf et al. 2010).

Antimony(III) trichloride also inhibited γ-radiation-induced DNA repair that correlated with disruption in the signaling cascade controlling the non-homologous end-joining repair (NHEJ) and homologous recombination-repair pathways (Koch et al. 2017). This impairment may be a consequence of antimony’s interaction with critical cysteines in ataxia-telangiectasia mutated kinase (ATM), or RAD51 DNA recombinase, or the zinc finger domain of BRCA1. How antimony influences the function of ATM, RAD51, and BRCA1 is not known.

Antimony(III) potassium tartrate inhibited the repair of UV-induced DNA damage and of γ-radiation-induced DNA double-strand breaks (DSBs) (to <10%) in CHO-K1 cells (Takahashi et al. 2002).

## 6.5 Alteration of Cell Proliferation and Receptor-mediated Effects

Antimony(III) trioxide has not been reported to inhibit apoptosis, increase cell proliferation, or encourage angiogenesis, but it increased the mutation of Egfr genes in mouse lung tumors.

Among the many receptors related to tumor development, the epidermal growth factor receptor gene (EGFR) (an oncogene) is commonly mutated in human lung neoplasms, and so is KRAS (a proto-oncogene), which does not code for a receptor but a G-protein influencing cells to divide or differentiate. The mutations of Egfr and Kras genes were analyzed in the lungs of mice and rats after 2-year inhalation exposure to antimony(III) trioxide at 3, 10, or 30 mg/m^3^ (NTP 2017a). Egfr mutations were seen in the lung tumors of mice (46% of the tissues) and rats (50% of the tissues), whereas no Egfr mutations were seen in non-tumorous lung tissue or in spontaneous lung tumors in the control animals. No Kras mutations were seen in the control rats, and only one Kras mutation was seen in a single lung tumor in antimony(III) trioxide-exposed rats. The incidences of Kras mutations in exposed mice were similar to those in control mice. These data suggest that EGFR signaling might play an important role in pulmonary carcinogenesis resulting from chronic antimony(III) trioxide exposure in both rats and mice (NTP 2017a). Detailed results of the studies are shown in Appendix E.4, Table E-5.

Antimony(III) potassium tartrate inhibits cell differentiation in cultured skin cells, potentially increasing the chance of tumor development, but in endothelial cells it decreases angiogenesis, which facilitates tumor growth. It is possible that antimony(III) potassium tartrate has both pro- and anti-tumorigenic effects.

In spontaneously immortalized keratinocytes (SIK), exposure to antimony(III) potassium tartrate prevented cell differentiation and preserved colony formation potential at 3 days post-confluence (Patterson and Rice 2007). Antimony(III) potassium tartrate preserved proliferation potential via preventing the decrease in EGFR caused by confluence or insulin in the media, and elevating β-catenin activity as a transcription factor, and preventing the decrease in active β-catenin level caused by confluence (Patterson and Rice 2007). The effects on EGFR were also seen in normal human foreskin epithelia cells (Patterson and Rice 2007). These findings may be relevant to antimony(III) trioxide-induced benign skin tumors (fibrous histiocytoma) in rats (see Section 5).

In cultured human umbilical-vein endothelial cells, antimony(III) potassium tartrate suppressed the activation of several critical receptor kinases involved in angiogenesis, including vascular endothelial growth factor receptor 2, fibroblast growth factor receptors 1 and 2, tyrosine kinase with immunoglobulin-like and epithelial growth factor-like domains 2, and erb-b2 receptor tyrosine kinase 2, at concentrations from 2.5 to 10 μmol/L (Wang et al. 2015). Moreover, antimony(III) potassium tartrate suppressed the phosphorylation of Src and focal adhesion kinase in the presence of phosphorylation triggers. In HepG2 (human liver carcinoma) cells, bis[(+)-tartato]diantimonate(III) dipotassium trihydrate (i.e., antimony(III) potassium tartrate trihydrate, equivalent to one molecule of antimony(III) potassium tartrate plus three water molecules), one of the top three affected regulators^1^ based on upstream analysis of the microarray data (see Appendix E.5, Table E-6) was vascular endothelial growth factor (VEGF). These findings support the notion that antimony(III) potassium tartrate has anti-angiogenic properties in endothelial cells; indeed, antimony(III) potassium tartrate inhibited vascularization of non-small-cell lung cancer xenografts in mice.

1 IPA (Ingenuity Pathway Analysis)’s definition of upstream transcriptional regulator is quite broad—any molecule that can affect the expression of other molecules, which means that upstream regulators can be almost any type of molecule, from transcription factor, to microRNA, kinase, compound or drug (Ingenuity Systems 2018). Consequently, the abbreviations in the discussion of upstream regulators do not necessarily follow the format rule of gene names in italic and protein names not.

## 6.6 Immunomodulation and Inflammation

Little is known regarding the effects of antimony(III) compounds on immunity. No in vivo or in vitro studies of antimony(III) trioxide effects on the immune system or function were found. In vitro exposure to an organic antimony(III) compound was found to affect expression of genes related to immune function, and in vivo intentional exposure to organic and inorganic antimony(V) compounds were used to increase immune response to parasites.

An epidemiological study (Kim et al. 1999) reported that workers exposed to high concentrations of antimony(III) trioxide in the air had altered activation of T and B cells and lowered serum cytokine and immunoglobulin (Ig) levels. However, this study did not control for potential confounding factors (e.g., exposure to co-contaminants that could affect immune function), so an association between antimony exposure and observed changes could not be confirmed.

In contrast to the lack of information of inorganic antimony immune effects, an organic compound containing antimony(III) was found to affect expression of many genes related to immune reactions. Based on the gene expression profile of HepG2 cells after 6-hour-exposure to bis[(+)-tartato]diantimonate(III) dipotassium trihydrate (equivalent to one molecule of antimony(III) potassium tartrate plus three water molecules) (Kawata et al. 2007) analyzed by ORoC (see Appendix E.5), of the top ten canonical pathways affected (see Table E-7), seven were related to immune reactions (agranulocyte adhesion and diapedesis, granulocyte adhesion and diapedesis, role of cytokines in mediating communication between immune cells, role of hypercytokinemia or hyperchemokinemia in the pathogenesis of influenza, crosstalk between dendritic cells and natural killer cells, role of interleukin-17A in psoriasis, and role of Wnt/GSK-3β signaling in the pathogenesis of influenza). These findings are consistent with the former use of antimony(III) potassium tartrate as an antiparasitic agent for leishmaniasis. In the upstream analysis (Appendix E.5, Table E-6), besides VEGF, the top three affected regulators were colony-stimulating factor 2 (CSF2) (a cytokine), and the triggering receptor expressed on myeloid cells 1 (TREM1), which stimulates neutrophil- and monocyte-mediated inflammatory responses. Both CSF2 and TREM1 stimulate immune or inflammatory responses.

The majority of studies investigating antimony-mediated effects on immunity involve humans and animals with parasite infections undergoing treatment with antimony(V) compounds. Antimony(V) compounds can potentiate inflammatory cytokine responses, macrophage activity, and expression of interferon-γ by T lymphocytes in vivo and in vitro (Appendix E.6, Table E-8). This immune-stimulating effect of antimony(V) may be in part from inhibition of Src homology PTPase1, a key phosphatase involved in regulating cytokine responses and immune-cell activation (Pathak and Yi 2001).

## 6.7 Epigenetic Alterations

Although there is some evidence for induction of epigenetic changes by antimony, the data are not sufficient to determine their contribution to the carcinogenicity of antimony(III) trioxide or antimony in general.

Only two studies on DNA and RNA methylation were identified, and none was specific for antimony(III) trioxide. This might reflect the relative newness of epigenetic research, besides DNA methylation, compared to other characteristics (particularly for genotoxicity and oxidative stress), rather than the degree or breadth of changes.

In a study of U.S. Native Americans, antimony exposure was linked to increased global methylation of cytosines and, to a lesser extent, increased global methylation of hydroxycytosines of DNA (Tellez-Plaza et al. 2014). Global hypomethylation has been reported to be associated with lung cancer (not from antimony exposure) (Daskalos et al. 2011; Daskalos et al. 2009) and cancer in general, but the change in methylation could also be risk-factor specific (Huang et al. 2016). Both increases and decreases in DNA methylation of various genes have been linked to carcinogenesis at various tissue sites (Lian et al. 2015; Witte et al. 2014), but the global change is less informative.

In cultured embryonic mouse stem cells, exposure to antimony(III) trichloride resulted in a decrease in the levels of modified cytidines, including 5-hydroxymethylcytosine, 5-formylcytosine, and 5-carboxylcytosine, in both DNA and RNA (Xiong et al. 2017). The decrease in 5-hydroxymethylcytosine has been reported to be associated with early stages of epigenetic carcinogenesis in rat liver (Lian et al. 2015).

## 6.8 Integration of Mechanistic Information

This section summarizes and integrates the primary findings from the mechanistic data on antimony(III) trioxide (Figure 6-2).

Figure 6-2

Key Mechanistic Information for Antimony(III) Trioxide Carcinogenicity

Because of its electrophilicity and affinity to vicinal thiol groups, antimony(III) trioxide is expected to be able to directly interact with GSH and many proteins that have DNA-binding domains, such as transcription factors and DNA repair enzymes. Indeed, these effects were seen with antimony(III) trioxide and other antimony compounds.

Generation of oxidative stress appears to be an early event in cells exposed to antimony. Antimony(III) trioxide induces ROS, disrupts mitochondrial membrane potential, and inhibits the enzymes involved in GSH functions, indicating that antimony disrupts enzymes and effectors of the cellular redox system. Excess oxidative stress can cause DNA damage, protein carbonylation, and lipid peroxidation, which were seen after exposure to meglumine antimoniate(V) in vivo.

Antimony(III) trioxide causes DNA damage, chromosomal aberrations, and micronucleus formation in rodents after in vivo exposure, Bacterial assays indicate it does not change the base-sequence in DNA, which is supported by the only available mammalian mutation study. Many studies have shown that various antimony compounds increase oxidative stress and cause oxidative damage. Antimony(III) trioxide also decreases levels of antioxidants in cells. Although antimony(III) trioxide was not used in the DNA repair study, two other antimony(III) compounds decreased DNA repair capacity in human cells in vitro, and the effect was due at least in part to displacement of the zinc(II) in zinc fingers of a DNA repair enzyme.

Antimony(III) trioxide causes mutations in Egfr in the lung tumors of mice and rats. Although antimony(III) potassium tartrate inhibits cell differentiation in cultured human skin cells (which is considered to preserve proliferation potential and thereby contribute to possible carcinogenicity) by preventing the decrease in EGFR activity when cells reach confluence, antimony(III) trioxide has not been reported to inhibit cell differentiation or increase cell proliferation.

In summary, based on studies using antimony(III) trioxide and other antimony(III) compounds, antimony(III) trioxide is electrophilic, can cause oxidative stress, likely inhibits DNA repair, can cause oxidative damage, and is likely to decrease cell differentiation. These effects can contribute to carcinogenesis, and all are biologically plausible in humans.