# 5 Studies of Cancer in Experimental Animals

This section reviews and assesses the evidence from carcinogenicity studies in experimental animals exposed to antimony(III) trioxide and applies the RoC listing criteria to reach a level-of-evidence conclusion of carcinogenicity.

Experimental animal carcinogenicity studies of antimony(III) trioxide were identified using methods described in the protocol and literature search strategy document (see Appendix A). Briefly, besides having a concurrent or historical control group, and reporting study design and results with sufficient detail, studies to be included need to meet one of the three following inclusion criteria (NTP 2015): (1) had an exposure duration of 12 months or greater for rats and mice and reported on the presence or absence of neoplastic and related nonneoplastic lesions (e.g., preneoplastic lesions or lesions considered part of the morphological continuum of neoplasia); (2) had a <12-month exposure, but showed increased neoplastic lesions; or (3) were cocarcinogen exposure studies (initiation/promotion and other cocarcinogen studies). Among 16 papers initially identified, four papers met the inclusion criteria. Among the 12 excluded papers, nine were not carcinogenicity studies, while three were carcinogenicity studies, but they tested antimony combined with nickel (Sunderman and McCully 1983; Sunderman et al. 1984; Sunderman Jr 1984). The effects from antimony alone cannot be identified for these papers, and thus these three papers were excluded.

Among the seven studies for antimony(III) trioxide reported in four papers (Groth et al. 1986; NTP 2017a; Newton et al. 1994; Watt 1983), five studies were used in this assessment. The study by Watt (1983) was a dissertation and not in the peer-reviewed literature, but it was cited in an IARC monograph (IARC 1989) and therefore considered peer reviewed by IARC. One of the two studies in Watt (1983) was excluded because the 1-year exposure in the miniature pig study did not cover a significant portion of the animal’s life span of 15 years (Ellegaard et al. 2010). One of two studies in the Groth et al. (1986) study was excluded due to having tested antimony ore that contained only 46% antimony, along with large amounts of other metals. In short, seven carcinogenicity studies in six journal articles and one carcinogenicity study in a dissertation were evaluated (Table 5-1).

Table 5-1 Experimental Animal Studies Evaluated for Carcinogenicity of Antimony(III) Trioxide

Species, Strain or Stock (Sex) | Route | Exposure/Whole-study Duration | Reference
Rat, Wistar Han (M&F) | Inhalation | 105 weeks/105 weeks | NTP (2017a)
Mouse, B6C3F1/N (M&F) | Inhalation | 105 weeks /105 weeks | NTP (2017a)
Rat, F344 (M&F) | Inhalation | 12 months/24 months | Newton et al. (1994)
Rat, CDF (F) | Inhalation | 1 year/2 years | Watt (1983)
Rat, Wistar (M&F) | Inhalation | 53 weeks /71–73 weeks | Groth et al. (1986)

Studies are presented in descending order of overall utility in informing carcinogenicity (see Section 5.2 and Table 5-2) Whole-study durations are combined exposure and post-exposure follow-up durations.

M = male; F = female.

Section 5 is organized by tumor site for tumors caused by exposure to antimony(III) trioxide. Section 5.1 provides an overview of the studies reviewed. Section 5.2 reports the quality of the included studies. Section 5.3 reports neoplastic findings (lung neoplasms in Section 5.3.1; other neoplasms (adrenal gland neoplasms, skin neoplasms, and lymphoma) in Section 5.3.2). Section 5.4 synthesizes findings across studies and provides NTP’s level-of-evidence conclusion.

## 5.1 Overview of the Studies

All five antimony trioxide carcinogenicity studies listed in Table 5-1 used inhalation exposure. Two studies exposed rats and mice for the whole duration of the study, 2 years, with interim sacrifice at 6 months and 12 months (NTP 2017a). Three studies exposed rats for approximately 1 year, followed by at least 4 months of post-exposure observation (Groth et al. 1986; Newton et al. 1994; Watt 1983). All studies used both sexes of rats or mice, except the Watt (1983) study, in which only female rats were used. The studies in rats were conducted in four different strains or stocks.

## 5.2 Study Quality Assessment

Each primary carcinogenicity study was systematically evaluated for its utility in informing the cancer hazard evaluation. A series of questions related to the following elements of study potential bias and study sensitivity were used: study design, exposure conditions, outcome, confounding, reporting, and analysis (NTP 2015). The following subsections discuss antimony(III) trioxide studies. Each study was evaluated individually and is presented in descending order of overall utility in determining carcinogenicity (Table 5-2). For details of each study assessment, see Appendix D.

Table 5-2 Quality Assessments of Antimony Trioxide Cancer Studies in Experimental Animals

Areas | NTP (2017a) | NTP (2017a) | Newton et al. (1994) | Watt (1983) | Groth et al. (1986)
Species | R | M | R | R | R
Sex | MF | MF | MF | F | MF
Study design
Animal randomization | +++ | +++ | +++ | NR | NR
Concurrent controls | +++ | +++ | +++ | +++ | +++
Animal model^a^ | +++ | +++ | +++ | ++ | +++
Statistical power^a^ | +++ | +++ | +++ | + | +++
Exposure
Chemical characterization | +++ | +++ | +++ | +++ | ++
Dosing regimen^a^ | +++ | +++ | ++ | +++ | ++
Exposure duration^a^ | +++ | +++ | +++ | +++ | ++
Dose/response | +++ | +++ | +++ | ++ | +
Outcome
Outcome methodology | +++ | +++ | ++ | ++ | +++
Group methodology consistency | +++ | +++ | +++ | +++ | ++
Adequacy of study duration^a^ | +++ | +++ | +++ | +++ | ++
Confounding
Consideration of confounding | +++ | +++ | +++ | ++ | +
Analysis and reporting
Reporting and statistics | +++ | +++ | +++ | ++ | +++
Tumor combining | +++ | +++ | +++ | +++ | +++
Study judgment
Overall utility | +++ | +++ | ++ | ++ | ++

In the row for species, R = rats, M = mice. In the row for sex, M = males, F = females. In rows for each signaling question, NR = not reported, +++ = high utility, ++ = moderate utility, + = low utility.

^a^ Elements related primarily to the sensitivity of the study.

All studies used concurrent negative controls, and two studies (NTP 2017a) also included historical control data. Two studies reported that animals were randomly assigned to treatment groups (NTP 2017a; Newton et al. 1994), while the older studies did not report whether randomization was performed. The study durations approached near life span durations in all but one study, Groth et al. (1986), which was less than a year and a half. Tumors were appropriately reported in all studies. The remaining ratings for study quality factors are reported in Table 5-2.

The two most recent antimony trioxide studies (NTP 2017a) presented no concerns regarding the utility to assess the cancer hazard and were considered of high overall utility.

Three antimony(III) trioxide studies were considered of moderate overall utility for assessing cancer hazard. The Groth et al. (1986) study used antimony(III) trioxide that was estimated to be 95.8% pure based on the assumption that all of the antimony (80% by weight) was in the trioxide form, which is consistent with the grade of antimony tested. Trace amounts of arsenic and lead contaminated the antimony(III) trioxide, but the low levels were not thought to contribute significantly to carcinogenicity. The Watt (1983) study used fewer than 10 CDF rats per group, limiting the statistical power of the study, and also used only females, eliminating the ability to detect cancer increases in males or differences between sexes. Furthermore, only a few organs were reported to have been examined during necropsy. The statistical methods used for tumor incidences were not reported. In the Newton et al. (1994) study, the highest exposure level caused no changes in body weight, survival, or tumor incidence, so the dose levels might not have reached the maximally tolerated dose.

## 5.3 Findings from Carcinogenicity Studies

Increased neoplastic lesions were observed in antimony(III) trioxide studies (see Table 5-3). Four of five studies showed increased neoplasms, and all four reported increases in lung neoplasms in rats or mice (Groth et al. 1986; NTP 2017a; Watt 1983). One study did not report an increase in neoplasms but did report an increase in preneoplastic lung lesions (Newton et al. 1994). The NTP studies (2017a) also reported increases in adrenal gland tumors in Wistar Han rats, and increases in lymphoma and skin tumors in B6C3F1/N mice. For detailed results at each tested concentration, see the second table in Section 5.4.2. Four studies were performed in rats; three studies were in both sexes (Groth et al. 1986; NTP 2017a; Newton et al. 1994) and one study was in just female rats (Watt 1983). One study was in mice of both sexes (NTP 2017a).

Table 5-3 Neoplasms Induced in Experimental Animal Carcinogenicity Studies of Inhaled Antimony(III) Trioxide

Species^a^, Strain or Stock | Site | Classification | Neoplasms (Sex of Animal) | Reference
Rat, Wistar Han | Adrenal gland | Benign | Pheochromocytoma (M and F) | NTP (2017a)
Rat, Wistar Han | Adrenal gland | Combined | Pheochromocytoma (F) | NTP (2017a)
Rat, Wistar Han | Lung | Benign | Alveolar/bronchiolar adenoma (M^b^ and F) | NTP (2017a)
Rat, Wistar Han | Lung | Combined | Alveolar/bronchiolar adenoma or carcinoma (M^b^) | NTP (2017a)
Mouse, B6C3F1/N | Lung | Benign | Alveolar/bronchiolar adenoma (F) | NTP (2017a)
Mouse, B6C3F1/N | Lung | Malignant | Alveolar/bronchiolar carcinoma (M and F) | NTP (2017a)
Mouse, B6C3F1/N | Lung | Combined | Alveolar/bronchiolar adenoma or carcinoma (F) | NTP (2017a)
Mouse, B6C3F1/N | Skin | Benign | Fibrous histiocytoma (M) | NTP (2017a)
Mouse, B6C3F1/N | Skin | Combined | Fibrous histiocytoma or fibrosarcoma (M) | NTP (2017a)
Mouse, B6C3F1/N | Whole body | Malignant | Lymphoma (F) | NTP (2017a)
Rat, Wistar | Lung | Benign | Bronchiolar/alveolar adenoma or carcinoma (F) | Groth et al. (1986)
Rat, Wistar | Lung | Malignant | Squamous-cell carcinoma (F) | Groth et al. (1986)
Rat, Wistar | Lung | Malignant | Scirrhous carcinoma (F) | Groth et al. (1986)
Rat, Fischer 344 | None | None | None (M and F) | Newton et al. (1994)
Rat (F only), CDF | Lung | Malignant | Scirrhous carcinoma (F) | Watt (1983)

Studies are presented in the order of descending overall utility.

In the Classification column, combined = benign or malignant (total number of animals with tumors).

F = female; M = male.

^a^ Both sexes, unless specified.

^b^ Considered evidence of antimony trioxide based on multiple factors, although the increase in incidence was not statistically significant.

### 5.3.1 Lung Neoplasms

Increased incidences of lung tumors were seen in three of the four rat studies and in the mouse study.

The NTP (2017a) 2-year study included a 1-year interim sacrifice in addition to the sacrifice at the end of the study. The NTP (2017a) study is discussed below in an order that follows the progression of lung tumor development, i.e., from preneoplastic hyperplasia to benign adenoma and then to malignant carcinoma.

Nonneoplastic lesions of the lung relevant to the carcinogenic process were increased in treated groups compared with vehicle controls. Both sexes of B6C3F1/N mice and Wistar Han rats had increased incidences of preneoplastic hyperplasia of alveolar and/or bronchiolar epithelium (see Table 5-4), in all exposed groups (3, 10, and 30 mg/m^3^) after 2 years (NTP 2017a).

Table 5-4 Lung Tumors in the Two-year NTP (2017a) Studies

| Antimony Trioxide Concentration
| 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Mouse
Pulmonary overload | No | Yes | Yes
Preneoplastic^a^ | ↑F, ↑M | ↑F, ↑M | ↑F, ↑M
Benign | ↑F | ↑F | ↑F
Malignant | ↑F, ↑M | ↑F, ↑M | ↑F, ↑M
Combined | ↑F, ↑M | ↑F, ↑M | ↑F, ↑M
Rat
Pulmonary overload | No | Yes | Yes
Preneoplastic^a^ | ↑F, ↑M | ↑F^b^, ↑M | ↑F^b^, ↑M
Benign | *M | ↑F, *M | ↑F^c^, *M
Malignant | – | – | –
Combined | *M | *M | *M

↑ = significant increase; F = in females; M = in males; * = considered evidence of antimony(III) trioxide carcinogenicity based on multiple factors, although the increase in incidence was not statistically significant.

^a^ Increased hyperplasia of both alveolar and bronchiolar epithelium.

^b^ Hyperplasia only increased in bronchiolar epithelium, not in alveolar epithelium.

^c^ Findings include an equivocal finding of benign cystic keratinizing epithelioma and some evidence for alveolar/bronchiolar adenoma.

Male Wistar Han rats exposed to 10 or 30 mg/m^3^ antimony(III) trioxide had higher incidences of alveolar/bronchiolar adenoma than control rats, but the difference was not statistically significant. The incidences did exceed the historical control incidences for inhalation studies. The incidence in the exposed rats might not have reached statistical significance, because the concurrent controls had exceeded the historical control incidence range for inhalation studies and studies by all routes. Furthermore, multiple alveolar/bronchiolar adenoma, not seen in controls, were observed at 3 and 30 mg/m^3^. While alveolar/bronchiolar carcinoma was seen in only two Wistar Han rats in the 10 mg/m^3^ group (not significantly increased), the incidences were zero (0) in the concurrent and historical controls. The combined incidences of alveolar/bronchiolar adenoma or carcinoma were increased in all treated groups of males. The observations above together with consideration of historical data and exposure-related increases in lung neoplasms in female Wistar Han rats and male and female B6C3F1/N mice, and the higher combined incidences of adenoma or carcinoma were considered to be some evidence of lung carcinogenicity in male Wistar Han rats (NTP 2017a).

In female Wistar Han rats, incidences of alveolar/bronchiolar adenoma, which were not seen in 300 historical control female Wistar Han rats, were higher (though not statistically significant) at 3 mg/m^3^ and were significantly increased at 10 and 30 mg/m^3^ in the 2-year study. Additionally, at the 12-month interim evaluation, one female Wistar Han rat exposed to 30 mg/m^3^ had alveolar/bronchiolar adenoma. Alveolar/bronchiolar adenoma is known to progress to carcinoma, but no alveolar/bronchiolar carcinoma was seen, and the combined incidence was not increased. The incidence of lung cystic keratinizing epithelioma or squamous-cell carcinoma combined was not significantly increased, but there was a significant positive trend and it was considered an equivocal finding. NTP (2017a) noted that “cystic keratinizing epitheliomas are considered part of a spectrum of lesions that form a continuum considered to progress from squamous metaplasia to keratin cysts to cystic keratinizing epithelioma to squamous-cell carcinoma.” NTP also reported lung squamous-cell carcinoma in male or female rats as part of the evidence for carcinogenicity of five substances with exposure by inhalation (tetranitromethane (NTP 1990), nickel(II) oxide (NTP 1996a), nickel subsulfide (NTP 1996b), cobalt sulfate heptahydrate (NTP 1998), and indium phosphide (NTP 2001)) and 2 substances with exposure by oral gavage (dimethyl hydrogen phosphide (NTP 1985) and 3,3',4,4',5-pentachlorobiphenyl (PCB 126), a type of polychlorinated biphenyl (PCB) compound (NTP 2006)).

Overall, these data were considered to be some evidence of carcinogenic activity in the lung based on benign alveolar/bronchiolar adenoma in female Wistar Han rats (NTP 2017a). Because the RoC listing criteria requires malignant and/or combined benign and malignant tumors in experimental animal studies, the findings in female Wistar Han rat lung do not meet the RoC listing criteria.

In the NTP (2017a) studies, as discussed in Section 3 (ADME), pulmonary overload was seen at 10 and 30 mg/m^3^, but not at 3 mg/m^3^ for both Wistar Han rats and B6C3F1/N mice, if the same criteria for increased clearance half-life are used for B6C3F1/N mice. At 3 mg/m^3^, benign lung tumors were increased in female B6C3F1/N mice, malignant lung tumors were increased in male and female B6C3F1/N mice, and combined benign and malignant lung neoplasms were increased in male Wistar Han rats and in male and female B6C3F1/N mice. Lung carcinogenesis occurring at 3 mg/m^3^, in all groups except female Wistar Han rats, indicates that pulmonary overload is not required to induce carcinogenesis and is supportive of the RoC listing criteria.

For mice, females in all treated groups showed increased incidences in alveolar and bronchiolar epithelium hyperplasia, alveolar/bronchiolar adenoma, alveolar/bronchiolar carcinoma, and alveolar/bronchiolar adenoma or carcinoma (combined) at 2 years. Carcinomas were increased in both sexes of mice and adenomas were increased in female mice. Compared to rats that had incidence rates of adenomas and carcinomas lower than 20% at all dose levels, mice had incidence rates that were all >20% and carcinomas that were over 60% at 30 mg/m^3^ in males. The incidences of carcinomas exceeded historical controls at all dose levels in both sexes and adenomas exceeded historical control at all dose levels in females. During the 1-year interim sacrifice a low frequency of alveolar/bronchiolar adenoma were seen in female mice. Males showed increased alveolar and bronchiolar epithelium hyperplasia in all treated groups, slightly (not significantly) higher incidence of alveolar/bronchiolar adenoma in the 3 and 30 mg/m^3^ groups, increased incidences of alveolar/bronchiolar carcinoma in all treated groups, and increased combined incidence of alveolar/bronchiolar adenoma or carcinoma in all treated groups after 2 years. After just 1 year, males had a low frequency of alveolar/bronchiolar adenoma and alveolar/bronchiolar carcinoma. These early findings indicate lung carcinogenesis related to antimony exposure (NTP 2017a). Significant increases in the incidences of adenomas and carcinomas were observed at exposure concentrations as low as 3 mg/m^3^, which did not cause pulmonary overload.

In the Groth et al. (1986) study, incidences of alveolar hyperplasia and cuboidal and columnar cell metaplasia were increased (statistical significance not reported) in female and male Wistar rats, and incidences of benign alveolar/bronchiolar adenoma as well as incidence of malignant lung neoplasms (squamous-cell carcinoma and scirrhous carcinoma) were increased significantly in female rats. Tumor incidences were not increased in male rats. Neoplasms occasionally developed from metaplastic foci, suggesting that metaplastic foci are preneoplastic. As mentioned above, the antimony(III) trioxide used in this study was only 80% pure and was contaminated with arsenic and lead. The concentrations of lead (0.1035 mg/m^3^) and arsenic (0.0018 mg/m^3^) in the air were both considered too low to have been the cause of neoplasms. Further, in animal studies, lead predominantly causes kidney neoplasms, which were not observed with antimony(III) trioxide exposure, thus, lead is not likely to have contributed to the carcinogenicity seen in the Groth et al. (1986) study. Arsenic causes mice and hamsters to develop lung neoplasms, which were seen in Wistar rats after exposure to antimony. Compared to the concentration of antimony(III) trioxide (36 mg/m^3^), the concentration of arsenic (0.0018 mg/m^3^) was inconsequential, which is further supported by (1) much higher levels of antimony than that of arsenic found in the lung in exposed animals (Table 5-5), and (2) higher levels of arsenic in the lung of males, which did not develop lung tumors, compared to that of females, which developed lung tumors.

Table 5-5 Antimony and Arsenic Concentrations (μg/g Freeze-dried Tissue) in the Lung and Blood of Wistar Rats Exposed to Antimony Trioxide Containing Arsenic by Inhalation

| Tissue Concentration (μg/g Freeze-dried Tissue) | | Ratio (Concentration in 45 mg/m^3^ group/concentration in 0 mg/m^3^ group)
Exposed antimony trioxide level | 0 mg/m^3^ | 45 mg/m^3^
Metal and site
Male
Antimony in lung | 9.2 | 38,300 | 4,163
Antimony in blood | 12.0 | 1,160 | 97
Arsenic in lung | 6.5 | 213 | 33
Arsenic in blood | 60.0 | 115 | <2
Female
Antimony in lung | 10.5 | 25,600 | 2,438
Antimony in blood | 9.6 | 1,034 | 108
Arsenic in lung | 18.5 | 150 | 8
Arsenic in blood | 123.0 | 230 | <2

Source: Groth et al. (1986).

The data in Table 5-5 suggest that neither arsenic nor lead contributed greatly to the observed incidences of lung cancer in this study, but interaction and other effects cannot be ruled out. Although this assessment is for hazard identification, it is noted that exposure concentrations in the Groth et al. (1986) study varied dramatically (average daily concentrations ranged from <10 mg/m^3^ to more than 80 mg/m^3^) due to technical difficulties in generating the aerosol, leading to questions about aerosol size and actual exposure level.

No increased incidences of neoplasms were observed in the 1-year exposure plus 1-year post-exposure recovery study in male and female F344 rats (Newton et al. 1994). The concentrations in that study, 0.06, 0.51, and 4.5 mg/m^3^, were much lower than the high concentrations used in previously discussed studies (i.e., 45 mg/m^3^ in Groth et al. (1986), and 30 mg/m^3^ in NTP (2017a)]) but the high concentration was comparable to the high dose used by Watt (1983) of 4.2 mg/m^3^. The aerosol size used in the Newton et al. (1994) study was large, ranging from 3.76 to 4.55 μm (depending on the instrument used) and included less respirable aerosols than if they had been <4.0 μm (OECD 2017; USEPA 1988). However, the Watt (1983) study used aerosols that were even larger, averaging 5.06 μm, and Watt reported significant increases in lung tumor incidences. Lungs appeared with pinpoint black foci, which the authors believed to be aggregates of macrophages containing antimony(III) trioxide. The strain or stock of rats also differs from that used in the positive studies.

Scirrhous carcinoma in the lung was increased in female CDF rats in a study with 1-year exposures at 4.2 mg/m^3^ (Watt 1983). It is worth noting that scirrhous carcinoma is not a term that NTP currently uses, and it is possible that the same lesions might be classified currently as alveolar/bronchiolar carcinoma. Exposed CDF rats also had significant increases in pneumocyte hyperplasia at 1.6 and 4.2 mg/m^3^, and adenomatous hyperplasia in the lung at 4.2 mg/m^3^.

### 5.3.2 Other Neoplasms

Besides lung neoplasms, benign or malignant pheochromocytoma of the adrenal gland in Wistar Han rats, and benign fibrous histiocytoma or malignant fibrosarcoma of the skin in B6C3F1/N mice, and malignant lymphoma in B6C3F1/N mice, also were increased after antimony(III) trioxide exposure (NTP 2017a).

#### Adrenal Gland Neoplasms

Pheochromocytoma of the adrenal medulla in benign and malignant forms were seen in Wistar Han rats, but not in B6C3F1/N mice, in the NTP (2017a) 2-year study.

Female Wistar Han rats in the 30 mg/m^3^ group had increased incidences of adrenal medullary hyperplasia, increased incidences of benign pheochromocytoma (which also exceeded historical control ranges), one incidence (not significantly increased) of malignant pheochromocytoma, and increased combined incidence of benign or malignant pheochromocytoma (see Table 5-6). Rats exposed to 3 and 10 mg/m^3^ had higher (but not significant) incidences of adrenal medullary hyperplasia, and the trend for all concentrations was positive. Overall, there is some evidence of adrenal medulla carcinogenicity in female Wistar Han rats (NTP 2017a). The increase in the combined incidences of benign or malignant pheochromocytoma in female Wistar Han rats supports the RoC listing criteria.

Table 5-6 Adrenal Medulla Neoplasms in Wistar Han Rats in the NTP (2017a) Two-year Study

| Antimony Trioxide Concentration
| 3 mg/m^3^ | 10 mg/m^3^ | 30 mg/m^3^
Observations
Pulmonary overload | No | Yes | Yes
Pre-neoplastic^a^ | *M | *F, *M | ↑F, ↑M
Benign | – | – | ↑F, ↑M
Malignant | – | – | –
Combined | – | – | ↑F

* = positive trend for dose response, although the increase in incidences was not statistically significant; ↑F = significant increase in females; ↑M = significant increase in males – = no increase reported.

^a^ Increased incidences of hyperplasia in adrenal medulla.

Male Wistar Han rats in the 30 mg/m^3^ group had increased incidences of adrenal medullary hyperplasia and increased incidences of benign pheochromocytoma. Incidences of benign pheochromocytoma at 10 mg/m^3^ were higher, but not significantly increased, compared to concurrent controls. Overall, there is some evidence of adrenal medullary carcinogenicity in female Wistar Han rats (NTP 2017a) based on the increased incidences of benign pheochromocytoma and combined malignant or benign pheochromocytoma.

Adrenal medullary hyperplasia and benign and malignant pheochromocytoma in Wistar Han rats have been seen in other NTP inhalation studies, although the mechanistic association remains unknown. Adrenal medulla pheochromocytoma is known to increase in rats under hypoxic conditions (Chandra et al. 2013). In the antimony(III) trioxide inhalation study (NTP 2017a), Wistar Han rats and B6C3F1/N mice showed abnormal breathing and Wistar Han rats also showed cyanosis in the second year. It is possible that lung-lesion-induced hypoxia chronically stimulates catecholamine secretion from the adrenal medulla, and the constant hypersecretion causes the adrenal medulla to develop hyperplasia (Gosney 1985) and subsequent pheochromocytoma (Ozaki et al. (2002) as cited in NTP (2017a)).

#### Skin Neoplasms

Skin neoplasms were seen in B6C3F1/N mice, but not in Wistar Han rats, in the NTP (2017a) 2-year study. Male B6C3F1/N mice had increased incidences (also exceeding historical control ranges) of benign fibrous histiocytoma at 30 mg/m^3^ and had a significant positive trend. Two incidences (not significantly increased) of malignant fibrosarcoma were seen at 10 mg/m^3^, and increased combined incidences of fibrous histiocytoma or fibrosarcoma at 30 mg/m^3^ which had a significant positive trend also occurred. Overall, there is some evidence of skin carcinogenicity in male B6C3F1/N mice based on increased combined incidences of fibrous histiocytoma or fibrosarcoma. Female B6C3F1/N mice had two incidences (not significantly increased but exceeding the historical control ranges) of squamous-cell carcinoma at 30 mg/m^3^, which was considered equivocal evidence of skin carcinogenesis in females.

#### Lymphomas

Increased incidences of malignant lymphoma were seen in female B6C3F1/N mice at all treatment concentrations (3, 10, and 30 mg/m^3^), with a significant positive dose-response trend after 2 years of exposure (NTP 2017a). The incidences at 10 and 30 mg/m^3^ also exceeded historical control ranges. After only 1 year of exposure, a low frequency of female mice developed lymphoma and almost all had lymphocyte infiltration into the lung. The 1-year finding demonstrates an early indication of the development of lymphoma. Preneoplastic proliferation of atypical lymphoid proliferation in the lung and spleen was also seen at the 1-year interim sacrifice. Overall, malignant lymphoma in female B6C3F1/N mice is considered to be clear evidence of carcinogenicity.

None of the other studies (Groth et al. 1986; Newton et al. 1994; Watt 1983) reported significant increases in the incidence of neoplasms other than the lung. Groth et al. (1986) examined most major organs while Newton et al. (1994) examined only a few organs. The extent of necropsy in the Watt (1983) study was not clearly reported. The Groth et al. (1986) and Newton et al. (1994) studies histologically examined the adrenal gland and skin and the Newton et al. (1994) study also examined lymph nodes, but none of these organs was found to have increased incidences of neoplasms. The lack of observed non-lung neoplasms was not due to a lack of examination of the target organ sites.

## 5.4 Synthesis and NTP’s Level-of-evidence Conclusion

### 5.4.1 Synthesis

The evidence for the carcinogenic potential from inhalation exposure to antimony(III) trioxide (Table 5-7 and Table 5-8) in experimental animals is strong.

Table 5-7 Neoplasms That Had Increased Incidences in Malignant Tumors or Combined (Benign or Malignant) Tumors

Sites | Rat | | Mouse
Sites | Malignant | Combined | Malignant | Combined
Lung | ↑F^a^ | *M^b^, ↑F^b^ | ↑M^c^, ↑F^c^ | ↑F^b^
Adrenal gland | – | ↑F^d^ | – | –
Skin | – | – | – | ↑M^e^
Lymphoma (whole body) | – | – | ↑F | –

↑ = significant increase; F = in females; * = considered evidence of antimony(III) trioxide carcinogenicity based on multiple factors, although the increase in incidence was not statistically significant (NTP 2017a); M = in males; – = no increase reported.

^a^ Squamous-cell carcinoma, scirrhous carcinoma.

^b^ Alveolar/bronchiolar adenoma or carcinoma.

^c^ Alveolar/bronchiolar carcinoma.

^d^ Benign or malignant pheochromocytoma.

^e^ Fibrous histiocytoma or fibrosarcoma.

Table 5-8 Cancer Studies in Experimental Animals from Exposure to Antimony(III) Trioxide

Reference and Study Design | Exposure | Tumor Site – Tumor Type | | Comments
Reference and Study Design | Exposure | Dose Levels (mg/m^3^) | Tumor Incidence (n/N) (%) | Comments
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | Agent and purity: Antimony(III) trioxide (crystalline form: crystalline, diamond cubic crystal structure) 99.9% Aerosol size: Mass median aerodynamic diameter (MMAD) 0.9–1.5 μm, GSD 1.7–2.2 Exposure route: Inhalation Exposure concentrations, frequency, and duration: 0 3 10 30 mg/m^3^ 6 hours/day, 5 days/week × 105 weeks | Adrenal gland – Benign pheochromocytoma^a^ | | Survival: Survival had a significant negative trend (p = 0.025) but was not significantly different compared to controls at any exposure level: 30/50, 30/50, 28/50, 18/50. Body weight: Body weight of the 30 mg/m^3^ group was lower than untreated controls after 69 weeks. Significantly increased preneoplastic lesions: Lung alveolar epithelium hyperplasia: 4/50, 50/50**, 48/50**, 49/50** Lung bronchiole epithelium hyperplasia: 3/50, 34/50**, 36/50**, 33/50** Adrenal medulla hyperplasia: 1/49, 2/50, 4/49, 8/50* Other comments: 12 Month interim evaluation: Perivascular lymphocytic infiltrate 0/10, 4/10*, 4/10*, 3/10. Overall utility: [+++] There were no concerns of confounding as the chemical was pure and stable, the exposure was well characterized, and all groups were treated the same. The study had a high level of sensitivity to detect neoplasms as it used large numbers of both sexes of rats, exposed at three dose levels, which reached the maximally tolerated level, for a near life span duration. However, the stock of rat used was new to NTP and so few historical control data exist compared to other strains. Complete necropsies with histological examination of most organs were performed, so the ability to detect neoplasms was high.
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 1/49 (2.5%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 0/50
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 2/49 (4.8%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 7/50*^b^ (17.2%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: < 0.001
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar adenoma^a^
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 3/50^c^ (7.1%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 4/50^c^ (9.8%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 6/50^c^ (13.8%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 8/50^c^ (19.7%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: = 0.057
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar carcinoma^a^
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/50
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 0/50
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 2/50^d^ (4.7%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 0/50
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar adenoma or carcinoma ^a^
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 3/50^c^ (7.1%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 4/50^c^ (9.8%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 8/50^c^ (18.4%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 8/50^c^ (19.7%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | Agent and purity: Antimony trioxide (crystalline form: crystalline, diamond cubic crystal structure) 99.9% Aerosol size: MMAD 0.9–1.5 μm, GSD 1.7–2.2 Exposure route: Inhalation Exposure concentrations, frequency, and duration: 0 3 10 30 mg/m^3^ 6 hours/day, 5 days/week × 105 weeks | Adrenal gland – Benign pheochromocytoma^a^ | | Survival: Survival was significantly decreased at 10 and 30 mg/m^3^ and there was a significant negative trend (p < 0.001): 39/50, 38/50, 28/50 (p = 0.032), 20/50 (p < 0.001). Body weight: Body weight was lower than controls in the groups exposed to 30, 10, and 3 mg/m^3^ after 65, 81, and 99 weeks, respectively. Significantly increased preneoplastic lesions: Lung alveolar epithelium hyperplasia: 5/50, 50/50**, 49/50**, 50/50** Lung bronchiole epithelium hyperplasia: 6/50, 26/50**, 25/50**, 27/50** Lung alveolar epithelium squamous metaplasia: 0/50, 5/50*, 3/50, 1/50 Adrenal medulla hyperplasia: 0/49, 0/49, 3/49, 5/50* Other comments: 12 Month interim evaluation: Alveolar/bronchiolar adenoma 0/10, 0/10 0/10, 1/10; Perivascular lymphocytic infiltrate 0/10, 4/10*, 5/10*, 3/10. Overall utility: [+++] There were no concerns of confounding as the chemical was pure and stable, the exposure was well characterized, and all groups were treated the same. The study had a high level of sensitivity to detect neoplasms as it used large numbers of both sexes of rats, exposed at three dose levels, which reached the maximally tolerated level, for a near life span duration. However, the stock of rat used was new to NTP and so few historical control data exist compared to other strains. Complete necropsies with histological examination of most organs were performed, so the ability to detect neoplasms was high.
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/49
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 2/49^e^ (4.5%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 2/49^e^ (4.8%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 6/50**^e^ (15.2%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: = 0.004
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Adrenal gland – Malignant pheochromocytoma
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/49
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 0/49
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 0/49
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 1/50 (2%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Adrenal gland – Benign or malignant pheochromocytoma^a^
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/49
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 2/49^f^ (4.5%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 2/49^f^ (4.8%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 7/50**^f^ (17.6%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: < 0.001
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar adenoma^a^
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/50
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 2/50^g^ (4.4%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 6/50*^g^ (13.8%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 5/50*^g^ (12.4%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: = 0.029
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Cystic keratinizing epithelioma or squamous-cell carcinoma^a,h^
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/50
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 0/50
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 0/50
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 3/50^g,h^ (7.4%)
NTP (2017a) Animal: Rat – Wistar Han [Crl:WI (Han)] F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: = 0.006
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | Agent and purity: Antimony(III) trioxide (crystalline form: crystalline, diamond cubic crystal structure) 99.9% Aerosol size: MMAD 0.9–1.5 μm, GSD 1.7–2.2 Exposure route: Inhalation Exposure concentrations, frequency, and duration: 0 3 10 30 mg/m^3^ 6 hours/day, 5 days/week × 105 weeks | Lung – Alveolar/bronchiolar adenoma^a^ | | Survival: Survival was significantly decreased at 10 and 30 mg/m^3^ and there was a significant negative trend (p < 0.001): 38/50, 30/50, 27/50 (p = 0.027), 17/50 (p < 0.001). Body weight: Body weights were lower than controls in the 30 mg/m^3^ group after 73 weeks. Significantly increased preneoplastic lesions: Lung lymphocyte infiltration: 13/50, 47/50^[^***^]^, 48/50^[^***^]^, 45/50^[^***^]^; Lung alveolar epithelium hyperplasia: 6/50, 39/50**, 45/50**, 49/50** Lung bronchiole epithelium hyperplasia: 0/50, 32/50**, 44/50**, 44/50**. Other comments: 12 Month interim evaluation: Alveolar/bronchiolar adenoma 0/10, 0/10, 2/10, 0/10; Alveolar/bronchiolar carcinoma 0/10, 0/10, 1/10, 2/10; Lung lymphocyte infiltration 0/10, 10/10**, 10/10**, 10/10**. Overall utility: [+++] There were no concerns of confounding as the chemical was pure and stable, the exposure was well characterized, and all groups were treated the same. The study had a high level of sensitivity to detect neoplasms as it used large numbers of both sexes of mice, exposed at three dose levels, which reached the maximally tolerated level, for a near life span duration. Complete necropsies with histological examination of most organs were performed, so the ability to detect neoplasms was high.
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 10/50 (21.5%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 14/50 (32.9%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 9/50 (21.8%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 14/50 (34.6%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar carcinoma^a^
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 4/50 (8.5%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 18/50***^i^ (40.9%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 20/50***^i^ (46.2%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 27/50***^i^ (62.8%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: < 0.001
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar carcinoma, multiple only
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 5/50* (10%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 6/50** (12%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 11/50** (22%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar adenoma or carcinoma^a^
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 13/50 (27.5%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 29/50*** (64.5%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 28/50*** (63.6%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 34/50*** (75.3%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: < 0.001
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Skin – Benign fibrous histiocytoma^a^
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 1/50^j^ (2.5%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 1/50^j^ (2.5%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 4/50*^j^ (10.6%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: = 0.012
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Skin – Fibrosarcoma
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 2/50^j^ (4%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Skin – Fibrous histiocytoma or fibrosarcoma^a^
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 1/50^k^ (2.5%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 3/50^k^ (7.3%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 4/50*^k^ (10.6%)
NTP (2017a) Animal: Mouse – B6C3F1/N M Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: = 0.023
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | Agent and purity: Antimony(III) trioxide (crystalline form: crystalline, diamond cubic crystal structure) 99.9% Aerosol size: MMAD 0.9–1.5 μm, GSD 1.7–2.2 Exposure route: Inhalation Exposure concentrations, frequency, and duration: 0 3 10 30 mg/m^3^ 6 hours/day, 5 days/week × 105 weeks | Whole body – Malignant lymphoma^a^ | | Survival: Survival was significantly decreased at 10 and 30 mg/m^3^ and there was a significant negative trend (p < 0.001): 36/50, 31/50, 26/50 (p = 0.032), 15/50 (p < 0.001). Body weight: Body weights were lower than controls in the 30 mg/m^3^ group after 85 weeks. Significantly increased preneoplastic lesions: Lung lymphocyte infiltration: 7/50, 37/50^[^***^]^, 37/50^[^***^]^, 26/50^[^***^]^; Lung alveolar epithelium hyperplasia: 1/50, 36/50**, 49/50**, 48/50** Lung bronchiole epithelium hyperplasia: 1/50, 34/50**, 48/50**, 45/50**. Other comments: 12 Month interim evaluation: Alveolar/bronchiolar adenoma 0/10, 0/10, 0/10, 1/10; peribronchial and perivascular lymphoid infiltrates 3/10, 10/10**, 10/10**, 9/10**; malignant lymphoma 0/10, /10, 0/10, 3/10. Overall utility: [+++] There were no concerns of confounding as the chemical was pure and stable, the exposure was well characterized, and all groups were treated the same. The study had a high level of sensitivity to detect neoplasms as it used large numbers of both sexes of mice, exposed at three dose levels, which reached the maximally tolerated level, for a near life span duration. Complete necropsies with histological examination of most organs were performed, so the ability to detect neoplasms was high.
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 7/50 (15.6%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 17/50*^l^ (38.1%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 20/50***^l^ (47.5%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 27/50***^l^ (60.7%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: < 0.001
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar adenoma^a^
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 1/50 (2.3%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 10/50**^m^ (22.8%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 19/50***^m^ (44.9%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 8/50**^m^ (20.3%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar carcinoma^a^
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 2/50 (4.4%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 14/50***^n^ (31.2%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 11/50**^n^ (26.8%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 11/50**^n^ (28.8%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar carcinoma, multiple only
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 7/50** (14%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 6/50* (12%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 4/50* (8%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Lung – Alveolar/bronchiolar adenoma or carcinoma^a^
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 3/50 (6.6%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 22/50***^o^ (48.8%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 27/50***^o^ (62.6%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 18/50***^o^ (43.5%)
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Trend p value: = 0.019
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | Skin – Squamous-cell carcinoma
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 0 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 3 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 10 | 0/50
NTP (2017a) Animal: Mouse – B6C3F1/N F Animal age at the beginning of exposure: 6 weeks Study duration: 105 weeks | | 30 | 2/50^p^ (4%)
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | Agent and purity: Antimony(III) trioxide (crystalline form: not reported) 80% (23 other metals, including Pb 2,300 μg/g; as 40 μg/g, and Ni 1.6 μg/g) Aerosol size: MMAD 2.80 μm Exposure route: Inhalation Exposure concentrations, frequency, and duration: 0 45 mg/m^3^ time-weighted average 7 hours/day, 5 days/week for 6 [5/sex], 9 [5/sex], and 12 [5/sex] months. After 53 weeks (~12 months) the remaining rats [75/sex] were kept unexposed for 18–20 additional weeks before sacrifice [Total time of 71–73 weeks]. Intermediate sacrifices were made to examine distribution of antimony in tissue. | Lung – Total neoplasms (M) | | Survival: Survival was similar to controls. Body weight: Body weights were similar to controls, although males did weigh 6.2% less than controls at 26 to 50 weeks. Significantly increased preneoplastic lesions: Interstitial fibrosis and alveolar-wall cell hypertrophy and hyperplasia, as well as cuboidal and columnar cell metaplasia occurred at lung foci. Occasionally, neoplasms developed from these foci, suggesting a pre-neoplastic lesion. Other comments: Total neoplasms included squamous-cell carcinoma, bronchioalveolar adenoma, bronchioalveolar carcinoma, and scirrhous carcinoma. Incidences of lung neoplasms were not reported in males but were said not to have been significantly different from controls. Overall utility: [++] The chemical was well characterized, but was found to be only 80% pure, with lead and arsenic as contaminants. The low purity makes distinguishing effects caused by antimony from possible effects caused by the contaminants difficult. The sensitivity of the study to detect neoplasms was low as only one dose level was used and it was based on the level of exposure to workers and not the maximally tolerated dose. Further, the exposure concentration varied widely until 5 months into the study when the target concentration was reached. The exposure duration was more than a year and full necropsies with histological examinations were performed. Neoplasms were reported with a statistical analysis as total neoplasms combined per organ site.
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 0 | None
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 45 | None
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | Lung – Total neoplasms (F)
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 0 | 0/89
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 45 | 19/89^[^***^]^ (21%)
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | Lung – Squamous-cell carcinoma (F)
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 0 | 0/89
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 45 | 9/89^[^**^]^ (10%)
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | Lung – Scirrhous carcinoma (F)
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 0 | 0/89
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 45 | 5/89^[^*^]^ (5.6%)
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | Lung – Bronchioalveolar adenoma or carcinoma combined (F)
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 0 | 0/89
Groth et al. (1986) Animal: Rat – Wistar M, F Animal age at the beginning of exposure: 8 months Study duration: 71 to 73 weeks | | 45 | 11/89^[^***^]^ (12%)
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) M Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | Agent and purity: Antimony(III) trioxide (crystalline form: not reported) 99.68% Aerosol size: MMAD = 3.76 ± 0.84 μm, GSD 1.79 ± 0.32 Exposure route: Inhalation Exposure concentrations, frequency, and duration: 0 0.06 (target 0.05) 0.51 (target 0.5) 4.50 mg/m^3^ (target 5.0) 6 hours/day, 5 days/week × 12 months 5 animals/sex were sacrificed at 6 (5/sex), 12 (5/sex), 18 (5/sex) months and the rest (50/sex) were sacrificed at 24 months. | Lung – Carcinoma | | Survival: Survival was similar to controls. Body weight: Similar to controls. Significantly increased preneoplastic lesions: Lungs were examined after 12 months and 24 months. 12 Month results: Alveolar/intraalveolar macrophage: 6/13 (46.2%), 11/13 (84.6%)[*], 9/12 (75.0%), 13/13 (100.0%)[**]; Alveolar/intraalveolar macrophage with foreign particulates: 0/13, 13/13 (100.0%)[***], 12/12 (100.0%)[***], 13/13 (100.0%)[***]; Perivascular/peribronchiolar macrophage with lymphoid cells and foreign particulates: 0/13, 2/13 (15.3%), 6/12 (50.0%)[**], 7/13 (53.8%)[**]; Peribronchial lymph node macrophage with foreign particulates: 0/13, 3/13 (23.1%), 5/12 (41.7%)[*], 13/13 (100.0%)[***]. 24 Month results: Interstitial inflammation: 32/52 (61.5%), 37/52 (71.2%), 36/53 (67.9%), 48/52 (92.3%)[***]; Bronchiolar/alveolar hyperplasia: 3/52 (5.8%), 1/52 (1.9%), 2/53 (3.8%), 4/52 (7.7%); Alveolar/intraalveolar macrophage: 31/52 (59.6%), 44/52 (84.6%)[**], 46/53 (86.8%)[**], 52/52 (100.0%)[***]; Alveolar/intraalveolar macrophage with foreign particulates: 0/52, 15/52 (28.8%)[***], 38/53 (71.7%)[***], 51/52 (98.1%)[***]; Perivascular/peribronchiolar macrophage with lymphoid cells and foreign particulates: 0/52, 22/52 (42.3%)[***], 46/53 (86.8%)[***], 47/52 (90.4%)[***]; Peribronchial lymph node macrophage with foreign particulates: 0/52, 6/52 (11.5%)[*], 34/53 (64.2%)[***], 39/52 (75.0%)[***]. Overall utility: [++] There was little concern for confounding as the chemical was pure, exposure conditions were well characterized, and groups were treated consistently with animals randomly assigned to exposure groups. The sensitivity of detecting neoplasms was good as high numbers of both sexes were tested. Exposures were at three concentrations for about half a life span duration (1 year), though observations (1 year) continued to a near life span total study duration. However, the highest exposure level did not reach the maximally tolerated level. Most organs were histologically examined, so most neoplasms would have been detected. Although aerosol size was not ideal (slightly over the current upper limit of test guidelines), this study did show Sb_2_O_3_ accumulation and decreased clearance in the lung (by 80% in the 4.5 mg/m^3^ group). The pulmonary overload was observed at relatively low exposure concentrations (compared to inert particles, such as TiO_2_) and Sb_2_O_3_ toxicity was suspected. It appears conditions that could lead to cancer did persist (Table 9, page 572 of Newton et al.), post-exposure, chronic inflammation in most animals, although hyperplasia was observed in very few animals).
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) M Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | | 0 | 1/52 (1.9%)
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) M Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | | 0.06 | 0/52 (0%)
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) M Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | | 0.51 | 0/53 (0%)
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) M Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | | 4.5 | 1/52 (1.9%)
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) F Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | Agent and purity: Antimony(III) trioxide (crystalline form: not reported) 99.68% Aerosol size: MMAD = 3.76 ± 0.84 μm, GSD 1.79 ± 0.32 Exposure route: Inhalation Exposure concentrations, frequency, and duration: 0 0.06 (target 0.05) 0.51 (target 0.5) 4.50 mg/m^3^ (target 5.0) 6 hours/day, 5 days/week × 12 months 5 animals/sex were sacrificed at 6 (5/sex), 12 (5/sex), 18 (5/sex) months and the rest (50/sex) were sacrificed at 24 months. | Lung – Carcinoma | | Survival: Survival was similar to controls. Body weight: Similar to controls. Significantly increased preneoplastic lesions: Lungs were examined after 12 months and 24 months. 12 Month results: Alveolar/intraalveolar macrophage: 6/16 (37.5%), 10/13 (76.9%)[*], 8/11 (72.7%), 14/14 (100.0%)[***]; Alveolar/intraalveolar macrophage with foreign particulates: 0/16, 13/13 (100.0%)[***], 11/11 (100.0%)[***], 14/14 (100.0%)[***]; Perivascular/peribronchiolar macrophage with lymphoid cells and foreign particulates: 0/16, 6/13 (46.2%)[**], 4/11 (36.4%)[*], 7/14 (50.0%)[**]; Peribronchial lymph node macrophage with foreign particulates: 0/16, 0/13, 6/11 (54.5%)[**], 13/14 (92.9%)[***]. 24 Month results: Interstitial inflammation: 33/49 (67.3%), 40/52 (76.9%), 48/54 (88.9%)[**], 48/50 (96.0%)[***]; Bronchiolar/alveolar hyperplasia: 1/49 (2.0%), 0/52, 0/54, 6/50 (12.0%); Alveolar/intraalveolar macrophage: 28/49 (57.1%), 40/52 (76.9%)[*], 48/54 (88.9%)[***], 50/50 (100.0%)[***]; Alveolar/intraalveolar macrophage with foreign particulates: 0/49, 24/52 (46.2%)[***], 49/54 (90.7%)[***], 48/50 (96.0%)[***]; Perivascular/peribronchiolar macrophage with lymphoid cells and foreign particulates: 0/49, 31/52 (59.6%)[***], 47/54 (87.0%)[***], 47/50 (94.0%)[***]; Peribronchial lymph node macrophage with foreign particulates: 0/49, 6/52 (11.5%)[*], 29/54 (53.7%)[***], 39/50 (78.0%)[***]. Overall utility: [++] There was little concern for confounding as the chemical was pure, exposure conditions were well characterized, and groups were treated consistently with animals randomly assigned to exposure groups. The sensitivity of detecting neoplasms was good as high numbers of both sexes were tested. Exposures were at three concentrations for about half a life span duration (1 year), though observations (1 year) continued to a near life span total study duration. However, the highest exposure level did not reach the maximally tolerated level. Most organs were histologically examined, so most neoplasms would have been detected. Although aerosol size was not ideal (slightly over the current upper limit of test guidelines), this study did show Sb_2_O_3_ accumulation and decreased clearance in the lung (by 80% in the 4.5 mg/m^3^ group). The pulmonary overload was observed at relatively low exposure concentrations (compared to inert particles, such as TiO_2_) and Sb_2_O_3_ toxicity was suspected. It appears conditions that could lead to cancer did persist (Table 9, post-exposure, chronic inflammation in most animals, although hyperplasia was observed in very few animals).
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) F Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | | 0 | 0/49 (0%)
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) F Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | | 0.06 | 0/52 (0%)
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) F Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | | 0.51 | 1/54 (1.9%)
Newton et al. (1994) Animal: Rat – Fischer 344 (CDF F344 Crl BR) F Animal age at the beginning of exposure: 8 weeks (140–169 g males; 99–122 g females) Study duration: 24 months | | 4.5 | 0/50 (0%)
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | Agent and purity: Antimony(III) trioxide (crystalline form: not reported) 99.4% Aerosol size: MMAD 5.06 μm Exposure route: Inhalation Exposure concentrations, frequency, and duration: 0 1.6 ± 1.5 [avg Feret’s diameter = 0.44 μm w/ geometric std dev 2.23] 4.2 ± 3.2 mg/m^3^ [avg Feret’s diameter = 0.4 μm w/ geometric std dev 2.13] for 6 hours/day, 5 days/week, for up to 1 year. Sacrifices at 0, 3, 6, 9, 12, and 24 months. | Lung – Scirrhous carcinoma | | Survival: Not reported. Body weight: Body weight gain in exposed rats was greater than controls. Significantly increased pre-neoplastic lesions: Lungs from exposed animals appeared grossly mottled—with foci of fibrosis. Focal fibrosis occurred as early as 3 months in the high dose group and the incidence was significantly increased over controls in the high dose group from 9 months to the end of the study and in the low dose group from 12 months to the end of the study. Significant increases in pneumocyte hyperplasia occurred in both the low and high dose from 12 months to the end of the study. Significant increases in adenomatous hyperplasia occurred in the high dose group after 9 months to the end of the study. The onset of multinucleated giant cells in the high dose group occurred after 6 months and in the low dose group after 1 year. Significant increases in the incidence of multinucleated giant cells were seen in the high dose group after 9 months and in the low dose group after 1 year. Other comments: Only the incidence at 2 years is reported here as the denominators of the other time points were all fewer than 10 rats. Scirrhous carcinomas were associated with an unusually large amount of fibrous connective tissue. Overall utility: [++] The chemical purity was high and exposure was characterized, although the particle size (converted by Newton et al. (1994) to be MMAD of ~5 μm) was over the recommended (1–4 μm). Only female rats were used, which eliminates the ability to detect sex differences. The sensitivity to detect neoplasms was low as a small number of rats were used at only two dose levels, though the exposure was near life span duration. The ability to detect neoplasms, if they exist, was moderate as the organs examined during necropsy were not fully reported. The statistical methods used were not reported. The use of large exposure chamber with pigs inside and pine shavings also increased the chance of exposure to non-Sb_2_O_3_ particles (and possible metabolism alternation due to pine shavings and therefore affecting susceptibility).
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | 0 | 0/13
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | 1.6 | 0/17
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | 4.2 | 9/18** (50%)
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | Lung – Squamous-cell carcinoma
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | 0 | 0/13
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | 1.6 | 0/17
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | 4.2 | 2/18 (11%)
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | Lung – Alveolar/bronchiolar adenoma
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | 0 | 0/13
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | 1.6 | 1/17 (5.9%)
Watt (1983) Animal: Rat – CDF F Animal age at the beginning of exposure: NR (Possibly 3 to 5 months) Study duration: 2 years | | 4.2 | 3/18 (16.7%)

* p < 0.05, **p < 0.01, ***p < 0.001.

[ ] = Statistical significance calculated by NTP, using Fisher’s Exact test.

Avg = average; F = female; GSD = geometric standard deviation; M = male; MMAD = mass median aerodynamic diameter; n/N = number of animals with neoplasms divided by the total number of animals tested in that group; NOS = not otherwise specified; NR = not reported; geometric std dev = standard deviation.

^a^ Adjusted percent incidence based on Poly-3 estimated neoplasm incidence after adjustment for concurrent mortality.

^b^ Exceeds historical controls from inhalation studies: 5/149 (range 0%–8%); exceeds historical controls from studies of all routes: 6/297 (range 0%–8%).

^c^ Exceeds historical controls from inhalation studies: 4/150 (range 0%–6%); exceeds historical controls from studies of all routes: 4/299 (range 0%–6%).

^d^ Exceeds historical controls from inhalation studies: 0/150; exceeds historical controls from studies of all routes: 0/299.

^e^ Exceeds historical controls from inhalation studies: 1/148 (range 0%–2%); exceeds historical controls from studies of all routes: 5/297 (range 0%–4%).

^f^ Exceeds historical controls from inhalation studies: 2/148 (range 0%–2%); exceeds historical controls from studies of all routes: 7/297 (range 0%–4%).

^g^ Exceeds historical controls from inhalation studies: 0/150; exceeds historical controls from studies of all routes: 0/300.

^h^ Includes two cystic keratinizing epithelioma and one squamous-cell carcinoma, tumors that NTP considered to be part of a continuum of lesions.

^i^ Exceeds historical controls from inhalation studies: 42/250 (range 8%–22%); exceeds historical controls from studies of all routes: 75/550 (range 4%–22%).

^j^ Exceeds historical controls from inhalation studies: 1/250 (range 0%–2%); exceeds historical controls from studies of all routes: 2/550 (range 0%–2%).

^k^ Exceeds historical controls from inhalation studies: 2/250 (range 0%–2%); exceeds historical controls from studies of all routes: 5/550 (range 0%–2%).

^l^ Exceeds historical controls from inhalation studies: 63/250 (range 14%–36%); exceeds historical controls from studies of all routes: 109/550 (range 12%–36%).

^m^ Exceeds historical controls from inhalation studies: 12/249 (range 2%–8%); exceeds historical controls from studies of all routes: 27/549 (range 0%–10%).

^n^ Exceeds historical controls from inhalation studies: 17/249 (range 2%–10%); exceeds historical controls from studies of all routes: 24/549 (range 0%–10%).

^o^ Exceeds historical controls from inhalation studies: 28/249 (range 6%–18%); exceeds historical controls from studies of all routes: 50/549 (range 2%–18%).

^p^ Exceeds historical controls from inhalation studies: 0/250; exceeds historical controls from studies of all routes: 0/550.

Four antimony trioxide inhalation studies have shown significant increases in the incidences of lung neoplasia in both sexes of rats or mice. Lung neoplasms included scirrhous carcinoma and squamous-cell carcinoma in female Wistar rats and scirrhous carcinoma in female CDF rats, alveolar/bronchiolar carcinoma in male or female B6C3F1/N mice, and alveolar/bronchiolar adenoma in male and female Wistar or Wistar Han rats and female B6C3F1/N mice. Combined incidences of alveolar/bronchiolar adenoma or carcinoma were increased in male Wistar Han rats and male and female B6C3F1/N mice.

Increased incidences of tumors outside the lung were seen in the NTP 2-year antimony(III) trioxide inhalation study (NTP 2017a) and included benign pheochromocytoma of the adrenal gland in male and female Wistar Han rats, combined benign and malignant pheochromocytoma in female Wistar Han rats, benign fibrous histiocytoma and combined fibrous histiocytoma and fibrosarcoma of the skin in male B6C3F1/N mice, and malignant lymphoma in female B6C3F1/N mice.

For all neoplasms, an increase in benign tumors only is not considered to support the RoC listing criteria, but an increase in malignant tumors only or an increase in combined incidences of benign or malignant tumor does meet the criteria. The latter increases were seen for four sites, three sites in rats (two sites in females, one in males) and two sites each in both male and female mice (Table 5-7).

### 5.4.2 NTP’s Level-of-evidence Conclusion

Sufficient evidence of carcinogenicity from studies in experimental animals based on the combined increase in the incidences of malignant and benign tumors at several tissue sites in rats and mice.