# 4 Human Cancer Studies

The objective of the cancer hazard evaluation of antimony(III) trioxide is to reach a level-of-evidence conclusion (sufficient, limited, or inadequate) for the carcinogenicity of antimony(III) trioxide from studies in humans by applying the RoC listing criteria to the body of evidence.

In general, the available human studies do not provide specific information on the antimony species to which occupational study populations were exposed; however, workers in antimony smelting and in art glass production were reportedly exposed to antimony(III) trioxide, as well as other antimony oxides and antimony sulfides. It is less clear what specific antimony species tin smelting workers were exposed to. Because specific antimony species or antimony groups are not available in human cancer studies, the generic term “antimony” is used in this section.

The cancer hazard evaluation of antimony primarily focuses on lung and stomach cancers because these were evaluated in multiple studies. (For rationale, see Antimony Protocol [NTP (2017b)] and Table 4-1).

Table 4-1 Antimony Exposure and Human Cancer Studies

Reference | Study Design (Location), Years, Population | Outcome, Including Cancer Sites, Data Analysis | Exposure: Antimony Compounds, Source of Information, Assessment, Metrics
Jones (1994) | Antimony smelter worker cohort (United Kingdom) 1961–1992 (study enrollment and follow-up period) N = 1,420 male workers | Historical mortality cohort (standardized mortality ratio [SMR]) All cancers; lung cancer; stomach cancer; other neoplasms (ICD-8 and ICD-9 codes: NR) All-cause and 7 noncancer sites | Smelting of antimony ore to antimony oxides and antimony alloys Company records Exposed: ever employed in U.K. antimony smelter External referent: local population Duration of employment, years of exposure, time of hire
Schnorr et al. (1995) | Antimony smelter worker cohort (United States) 1937–1989 (employment and follow-up period) N = 1,014 male workers | Historical mortality cohort (SMR) Cancers in trachea, bronchus, lung (ICD-9 code: 161); stomach cancer (ICD-9 code: 151); all cancer; 9 other site-specific cancers All-cause and 14 noncancer sites | Antimony ore (oxide and sulfide), metal, and antimony oxides Company records Exposed: ever employed in U.S. antimony smelter External referents: national and ethnic-specific local U.S. population Duration of employment
Jones et al. (2007); methods described in Binks et al. (2005) | Tin smelter worker cohort (United Kingdom) 1937–2001 (employment and follow-up period) N = 1,462 male workers | Poisson regression analysis (relative risk [RR]) Lung cancer (ICD-8 code: 162.0–162.1 and ICD-9 code: 162.0–162.9) | Antimony species NR Exposure sources: area and personal air sampling, personnel records, JEM Quantitative cumulative inhalation exposure (mg-year/m^3^)
Wingren and Axelson (1993); methods described in Wingren and Axelson (1985) | Case-control study of men in art glass-producing area (Sweden) 1950–1982 (mortality period) N for cases and controls = NR | Case-control analysis (OR) Cases: stomach cancer (ICD-8 code: 151); colon cancer (code: NR) Controls: death other than cancer or cardiovascular disease | Antimony(III) trioxide Exposure status: Determined by listed occupation in death registry Intensity (based on glass works consumption patterns)

ICD = International Classification of Diseases, ICD-8 = ICD Revision 8 (1965), ICD-9 = ICD Revision 9 (1978), JEM = job-exposure matrix, NR = not reported, OR = odds ratio, RR = relative risk, SMR = standardized mortality ratio, U.K. = United Kingdom, U.S. = United States.

The steps in the cancer hazard evaluation are presented in this section as below.

1. Selection and overview of the human cancer studies (Section 4.1 and Antimony Protocol [NTP (2017b)]).
2. Evaluation of risk of bias and study sensitivity (Section 4.2, and Appendix C, Table C-1, Table C-2, Table C-3, Table C-4, Table C-5, Table C-6).
3. Cancer hazard assessment: lung cancer (Section 4.3.1), stomach (Section 4.3.2), and other cancers (Section 4.3.3).
4. NTP’s level-of-evidence conclusion for carcinogenicity (sufficient, limited, or inadequate) of antimony from human studies (Section 4.4).

## 4.1 Selection of the Relevant Literature and Overview of the Study Characteristics

Procedures to identify and select the primary studies and supporting literature for the human cancer evaluation are detailed in Section 3 of the Antimony Protocol (NTP 2017b).

Briefly, primary epidemiological studies were considered for the cancer evaluation if the study (1) was peer reviewed; (2) provided risk estimates (or sufficient information to calculate risk estimates) for antimony and human cancer; and (3) provided exposure-specific analyses for antimony at an individual level, or, based on the authors’ report, antimony exposure was probable or predominant in the population, job, or occupation under study. Both cohort and case-control studies, but not ecological or other types of epidemiological studies, of antimony were found to fit these criteria and therefore were included for evaluation.

A U.S. population-based cohort study on urinary antimony concentrations and cancer (Guo et al. 2016) and a Turkish geospatial study on antimony exposure from drinking water and cancer incidence (Colak et al. 2015) were excluded from the cancer evaluation because only all malignant neoplasms, not site-specific cancers, were reported. Two Swedish post-mortem studies comparing antimony concentrations in various tissue types in deceased metal smelter workers and deceased controls (Gerhardsson et al. 1982; Gerhardsson and Nordberg 1993) were excluded because no point estimates were reported and exposure measurements did not precede cancer outcomes.

The available epidemiological studies that satisfy the criteria for consideration in the cancer evaluations are three occupational cohort studies (Jones 1994; Jones et al. 2007; Schnorr et al. 1995; Wingren and Axelson 1993) and one case-control study (Wingren and Axelson 1993) conducted in four independent populations. These were two antimony smelting cohorts in the United Kingdom and the United States, a tin smelting cohort in the United Kingdom, and a case-control study from an art glass region in Sweden. Detailed data on study design, methods, and findings for each of the available studies are provided in the table in Section 4.3.

In both cohort and case-control studies, participants were occupationally exposed to antimony via metal smelting (Jones 1994; Jones et al. 2007; Schnorr et al. 1995) or art glass manufacturing (Wingren and Axelson 1993). Ever-exposure to antimony was characterized by occupational status based on company records (Jones 1994; Schnorr et al. 1995) or listed occupation on mortality records (Wingren and Axelson 1993). Only Jones et al. (2007) established a job-exposure matrix (JEM) based on personnel work histories and both area and personal air sampling measurements for antimony and four other heavy metals.

The likely antimony species to which workers were occupationally exposed were antimony(III) trioxide in art glass workers (Jones 1994; Schnorr et al. 1995; Wingren and Axelson 1993) and, with less certainty, tin smelter workers (Jones et al. 2007), as well as other antimony oxides and antimony sulfides in antimony smelter workers (Jones 1994; Schnorr et al. 1995). In three of the four studies (Jones 1994; Schnorr et al. 1995; Wingren and Axelson 1993), the levels of exposure to antimony alone were not defined in enough detail to explore exposure-response relationships. Jones et al. (2007) did model a linear exposure-response relationship between antimony air concentrations and lung cancer mortality.

All studies examined cancer mortality. All cohort studies reported lung cancer mortality (Jones 1994; Jones et al. 2007; Schnorr et al. 1995), and two cohort studies and one case-control study reported on gastric cancer mortality (Jones 1994; Schnorr et al. 1995; Wingren and Axelson 1993). All studies used the International Classification of Diseases (ICD) coding schemes based on death certificates or death registries. Jones (1994) reported mortalities from all causes, from noncancer cardiovascular, respiratory, and urinary diseases, and from accidental causes. Besides lung and stomach cancer, other malignant neoplasms in antimony smelter workers were reported without specific cancer site information. Schnorr et al. (1995) also examined mortality from all causes, all cancers, and cancers from all digestive system, all respiratory system, and specific sites (i.e., stomach; liver and gallbladder; colorectal; buccal cavity and pharynx; trachea, bronchus, and lung; urinary organs; lymphatic and hematopoietic tissues; and male genital organs). Additionally, the study reported 14 other major noncancer causes of death in the United States, including pneumoconiosis. In addition to stomach cancer mortality cases, Wingren and Axelson (1993) conducted analyses for lung and colon cancer cases using a Swedish death registry, but they only published risk estimates for colon cancer.

Given the reported cancer sites in the available studies, lung and stomach were chosen as focal cancer sites for the current evaluation. The study methods and characteristics of each study are described in Table 4-1.

## 4.2 Study Quality and Utility Evaluation

This section assesses the adequacy of the identified cohort and case-control studies to evaluate cancer hazard of antimony. This assessment considers factors relating to study quality (potential for selection and attrition bias, information bias regarding exposure and outcome, and concern for inadequate analytical methods, selective reporting, and inadequate methods or information to evaluate confounding) and study sensitivity (e.g., adequate numbers of individuals exposed to substantial levels of antimony). The ratings for each of these factors are provided in Table 4-2 and the rationale for the rating is described in detail in Appendix C Table C-1, Table C-2, Table C-3, Table C-4, Table C-5, Table C-6.

Table 4-2 Summary of Ratings for Concerns for Potential Bias, Study Quality, and Study Utility in Antimony Epidemiology Studies

Study Type, Citation | Concern for Potential Bias^a^ | | | | | | Quality^a^ | Utility^b^
Study Type, Citation | Selection | Exposure | Outcome | Confounding Methods | Adequacy of Analysis | Selective Reporting | Sensitivity | Integration
Cohort studies
Antimony smelter workers
Jones (1994) | ++ | +++/++ | +++ | + | +++ | +++ | ++ | +++/++
Schnorr et al. (1995) | ++ | ++ | +++ | +++ | ++ | +++ | ++ | +++/++
Tin smelter workers
Jones et al. (2007) | ++ | ++ | +++ | ++ | ++ | +++ | + | ++
Case-control study
Wingren and Axelson (1993) | +++ | + | ++ | + | ++ | ++ | + | +

^a^ Levels of concern for bias and for study quality rating. Equal column width for types of bias does not imply they have equal weight (see RoC Handbook (https://ntp.niehs.nih.gov/pubhealth/roc/handbook/index.html) for description of terms): +++ = low/minimal concern or high quality; +++/++ = minimal/some concern or high/medium quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

^b^ Utility of the study to inform the hazard evaluation (see RoC Handbook (https://ntp.niehs.nih.gov/pubhealth/roc/handbook/index.html) for description of terms): +++ = high utility; +++/++ = high/moderate utility; ++ = moderate utility; ++/+ = moderate/low utility; + = low utility; 0 = inadequate utility.

No critical concerns for the potential for any of the bias domains were identified in the available studies; thus, each study may be informative for evaluating potential cancer hazards. The occupational cohort and case-control populations had small numbers of exposed cancer deaths, and, therefore, suffered from low statistical power. Table 4-2 depicts the overall assessment of the ability to inform the cancer evaluation based on the overall utility of the studies, including potential for biases and study sensitivity.

All three retrospective cohort studies (Jones 1994; Jones et al. 2007; Schnorr et al. 1995) had low risk of selection bias because they all had clearly defined cohorts by exposure status during specific time periods and geographic locations associated with the antimony and tin smelters. All cohort studies had minimal (3.0% to 5.7%) loss to follow-up and relied on death certificates to trace workers’ outcome status. Bias due to healthy worker survival effect (HWSE) is possible in all studies, though unlikely. Observed all-cause mortality rates in study participants did not differ from the general population. All three cohort studies enrolled workers already employed by the smelter companies and likely already exposed to antimony before enrollment, although all three studies accounted for time since exposure in their analyses.

The cohort studies of metal smelter workers (Jones 1994; Jones et al. 2007; Schnorr et al. 1995) were deemed to have some concern for non-differential exposure misclassification, and the case-control study of Swedish art glass workers (Wingren and Axelson 1993) had major concerns for exposure misclassification (see Appendix C, Table C-2). Reasons for these concerns include lack of individual-level exposure data (Jones et al. 2007; Wingren and Axelson 1993), lack of exposure information prior to enrollment date, and reliance on ever-exposure to antimony. Furthermore, antimony exposure likely varied over time as changes in occupational smelting practices and different source materials were reported in studies. To better characterize exposure, reliance on job titles (Jones 1994) and worker functions (Jones et al. 2007) allowed for greater specificity. It should be noted that while individual-level exposure estimates are generally more precise than imprecise group-level estimates, they may be more subject to bias which may impact the validity of the results (Tielemans et al. 1998). Regardless, exposure misclassification in all four studies is non-differential and would likely attenuate effect estimates.

Major concerns for confounding bias were found in studies of antimony smelter workers (Jones 1994) and the art glass worker case-control study (Wingren and Axelson 1993), some concern in the study of tin smelter workers (Jones et al. 2007), and minimal concern in the study of antimony smelter workers (Schnorr et al. 1995) (see Appendix C, Table C-5). No studies controlled for lifestyle-related confounders such as smoking, or occupational co-exposures, e.g., arsenic, lead, asbestos, or polycyclic aromatic hydrocarbons (PAHs). Although smoking prevalence was not directly controlled for in the three occupational cohort studies, smoking rates were assessed. Occupational co-exposure to lead, arsenic, and PAHs were identified or concurrently examined, but were not adequately controlled for in all occupational metal-working cohorts; however, in some studies, available monitoring data on co-exposures and antimony helped inform the evaluation of confounding bias. Lead and asbestos were suspected occupational co-exposures in the case-control study involving art glass workers. Given there is either some concern (Jones et al. 2007) or major concern (Jones 1994; Wingren and Axelson 1993) for confounding bias in most studies (a noted exception is minimal concern for confounding bias in Schnorr et al. (1995)), reported estimates of antimony exposure and both lung and stomach cancer mortalities may be confounded by smoking and/or occupational co-exposures.

The available studies on antimony exposure had low, moderate, or moderate-to-high utility in informing a cancer hazard evaluation (Table 4-2).

Two studies of antimony smelter workers (Jones 1994; Schnorr et al. 1995) were judged to have moderate-to-high study utility based on potential biases and moderate concern for study sensitivity. A critical factor lowering the utility for informing a cancer hazard was potential confounding from co-exposures to known carcinogens for lung and stomach cancers.

The cohort of tin smelter workers (Jones et al. 2007) was rated as having moderate study utility, with moderate concerns for exposure misclassification and confounding, and major concerns for study sensitivity. The Swedish-based case-control study (Wingren and Axelson 1985) was rated as having low study utility due to major concerns for potential exposure misclassification, confounding bias from occupational co-exposures, and major concerns for study sensitivity.

## 4.3 Cancer Hazard Assessment

The primary cancer sites evaluated are lung (Section 4.3.1) and stomach cancers (Section 4.3.2). Other cancer sites are briefly summarized in Section 4.3.3.

### 4.3.1 Lung Cancer

Among all cancers, lung cancer has the highest mortality rate and the third highest incidence rate in the United States. From 1975 to 2014, age-adjusted incidence rates per 100,000 people were 84.2 for men and 46.3 for women in the general U.S. population (see Table 15.6 of Howlader et al. (2017)). Lung cancer mortality rates are comparable to their respective incidence rates given the low 5-year survival rate (18.1%) based on 2007 to 2013 age-adjusted data (Table 15.12 of Howlader et al. (2017)), suggesting incidence and mortality data may have similar ability to inform a cancer evaluation.

Potential confounders evaluated in relevant antimony exposure studies include occupational co-exposures and non-occupational exposures or lifestyle factors. Among antimony smelters or glass workers, lung carcinogens most likely to be present in the occupational setting include arsenic and lead and, to a lesser extent, PAHs and asbestos (IARC 2017a).

#### Evidence from Individual Studies

The available occupational cohort studies of antimony and lung cancer include a cohort of U.K. antimony smelter workers, a cohort of U.S. antimony smelter workers, and a cohort of U.K. tin smelter workers. Based on the study quality evaluation, these three studies were considered to be informative for inclusion in the cancer assessment. The findings from individual studies are discussed below and presented in Table 4-3.

Table 4-3 Evidence from Epidemiological Cohort and Case-control Studies on Lung and Stomach Cancers and Exposure to Antimony

Reference, Location, Study Design and Year | Population Description & Exposure Assessment Method | Exposure Category | Risk Estimate (95% CI) | Exposed Cases | Covariates | Comments, Strengths, and Limitations
Jones (1994) Cohort Northeast England, United Kingdom Enrollment or follow-up: 1961–1992 (study enrollment and follow-up period) | Population: Antimony smelter workers N = 1,420 men Exposure assessment method: company records | Lung cancer: Ever employed antimony workers, SMR (95% CI) | | | Age | Exposure information: Exposure level: Ever-exposure to antimony defined as employment in antimony plant for 3+ months. Exposure duration: 6–50 years based on employment. Confounding concern: Likely co-exposure to arsenic and PAHs (lung carcinogens). Smoking not controlled for despite 72% prevalence. Strengths: Antimony workers exposed primarily to antimony compounds. Stratified by hiring date, years since first exposure. Additional analysis on other job titles. Limitations: External analysis only. Small number of exposed cases for lung and stomach cancers. Potential confounding by smoking and occupational co-exposures. Individual-level data on exposure not available. Level of evidence: Inconclusive (lung), inconclusive (stomach)
Jones (1994) Cohort Northeast England, United Kingdom Enrollment or follow-up: 1961–1992 (study enrollment and follow-up period) | Population: Antimony smelter workers N = 1,420 men Exposure assessment method: company records | Ever antimony worker | [1.55 (1.11–2.11)] | 37 | Age
Jones (1994) Cohort Northeast England, United Kingdom Enrollment or follow-up: 1961–1992 (study enrollment and follow-up period) | Population: Antimony smelter workers N = 1,420 men Exposure assessment method: company records | Before 1/1/1961 | [2.18 (1.49–3.07)] | 32 | Age
Jones (1994) Cohort Northeast England, United Kingdom Enrollment or follow-up: 1961–1992 (study enrollment and follow-up period) | Population: Antimony smelter workers N = 1,420 men Exposure assessment method: company records | After 12/31/1960 | [0.54 (0.18–1.27)] | 5 | Age
Jones (1994) Cohort Northeast England, United Kingdom Enrollment or follow-up: 1961–1992 (study enrollment and follow-up period) | Population: Antimony smelter workers N = 1,420 men Exposure assessment method: company records | Stomach cancer: Ever employed antimony workers, SMR (95% CI) | | | Age
Jones (1994) Cohort Northeast England, United Kingdom Enrollment or follow-up: 1961–1992 (study enrollment and follow-up period) | Population: Antimony smelter workers N = 1,420 men Exposure assessment method: company records | Ever antimony worker | [0.42 (0.05–1.51)] | 2 | Age
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | Lung cancer: External analysis – U.S. white male mortality rates, SMR (95% CI) | | | Age, calendar year, latency period | Exposure information: Exposure level: Ever-exposure to antimony defined as employment in antimony plant for 3+ months from 1937–1971. Exposure duration: <5 years to >10 years based on employment. Confounding concern: Minimal concern from smoking, arsenic, and lead exposure. Strengths: Antimony workers primarily exposed to antimony compounds; both national and local ethnic-specific expected mortality rates were calculated; two-time air sampling of antimony and arsenic. Limitations: External analysis only; small number of exposed cases for lung and stomach cancers; individual-level data on exposure not available. Level of evidence: Some evidence (lung); some evidence (stomach)
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | Ever antimony worker | [0.75 (0.51–1.07)] | 30 | Age, calendar year, latency period
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | Lung cancer: External analysis – Texas ethnic-specific mortality rates, SMR (90% CI) | | | Age, calendar year, latency period
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | Ever antimony worker | 1.39 (1.01–1.88) | 28 | Age, calendar year, latency period
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | <5 years employment | SMR only: 0.83 | 11 | Age, calendar year, latency period
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | 5–10 years employment | SMR only: 2.24 | 8 | Age, calendar year, latency period
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | >10 years employment | SMR only: 2.73 | 9 | Age, calendar year, latency period
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | Stomach cancer: External analysis – U.S. white male mortality rates, SMR (95% CI) | | | Age, calendar year, latency period
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | Ever antimony worker | 1.49 (0.71–2.74) | 10 | Age, calendar year, latency period
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | Stomach cancer: External analysis – Texas ethnic-specific mortality rates, SMR (95% CI) | | | Age, calendar year, latency period
Schnorr et al. (1995) Cohort Southern Texas, United States Enrollment or follow-up: 1937–1989 (employment and follow-up period) | Population: Antimony smelter workers N = 1,014 men Exposure assessment method: company records | Ever antimony worker | 1.24 (0.50–2.55) | 7 | Age, calendar year, latency period
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Lung cancer: Cumulative exposure, RR (90% CI) | | | Age, calendar year, time since exposure | Exposure information: Exposure level: cumulative antimony inhalation over employment duration. Exposure duration: Modeled three exposure scenarios from 1937–1971 using annual air sampling estimates from 1972–1991. Confounding concern: Highly correlated antimony, lead, and arsenic air concentrations; minimal concern for smoking, but not controlled for in analysis. Strengths: Concentration-response relationship examined; use of JEM from work histories and 20 years of air measurements; antimony exposure cumulatively estimated. Limitations: Small number of exposed cases for lung cancer. No information on smoking status; did not control for highly correlated occupational co-exposures. Exposure not at an individual level; air concentrations modeled over 34-year period. Level of evidence: Inconclusive (lung)
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 1a (unweighted) | [1.23 (0.79–1.92)] | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 1a (weighted) | [5.26 (1.75–43.38)] | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 2b (unweighted) | [1.13 (0.80–1.60)] | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 2b (weighted) | [3.25 (1.32–21.76)] | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 3c (unweighted) | [1.12 (0.80–1.55)] | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 3c (weighted) | [3.32 (1.42–8.08)] | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Lung cancer: Cumulative exposure, beta coefficient (β) (90% CI) | | | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 1^a^ (unweighted) | 0.21 (−0.24–0.65) | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 1^a^ (weighted) | 1.66 (0.56–3.77) | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 2^b^ (unweighted) | 0.12 (0.22–0.47) | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 2^b^ (weighted) | 1.18 (0.28–3.08) | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 3^c^ (unweighted) | 0.11 (−0.22–0.44) | 62 | Age, calendar year, time since exposure
Jones et al. (2007) Cohort Northern England, United Kingdom Enrollment or follow-up: 1937–2001 (Employment and follow-up period) | Population: Tin smelter workers N = 1,462 men Exposure assessment method: job-exposure matrix and air sampling measurements | Model 3^c^ (weighted) | 1.20 (0.35–2.09) | 62 | Age, calendar year, time since exposure
Wingren and Axelson (1993) Case-control Southeast Sweden Enrollment or follow-up: 1950–1982 (mortality period) | Population: Population-based study of art glass producing area N cases = NR (~ 73 cases of stomach cancer, Wingren and Axelson (1985)). N controls: NR (~833 controls, Wingren and Axelson (1985)) Exposure assessment method: occupation (i.e., art glass worker) listed on death records | Stomach cancer: Antimony use in parish of subject death, OR (90% CI) | | | Age | Exposure information: Occupation listed as glass worker on death record, and subject died in a parish where antimony use was reported. Exposure level: Reported antimony usage levels from companies within study’s geographic area. Confounding concern: Likely co-exposure to lead; minimal concern for smoking and asbestos. Strengths: Population-based study; cases and controls from same geographic area. Limitations: Unknown number of cases and controls; exposure status based on factory antimony use at one time point; likely confounding from occupational co-exposure to lead. Level of evidence: Inconclusive (stomach)
Wingren and Axelson (1993) Case-control Southeast Sweden Enrollment or follow-up: 1950–1982 (mortality period) | | No use | 2.00 (1.30–3.10) | NR | Age
Wingren and Axelson (1993) Case-control Southeast Sweden Enrollment or follow-up: 1950–1982 (mortality period) | | Low level of use | 1.60 (0.90–2.60) | NR | Age
Wingren and Axelson (1993) Case-control Southeast Sweden Enrollment or follow-up: 1950–1982 (mortality period) | | High level of use | 0.80 (0.30–2.00) | NR | Age
Wingren and Axelson (1993) Case-control Southeast Sweden Enrollment or follow-up: 1950–1982 (mortality period) | | Any level of use (pooled estimate) | [1.36 (0.85 to 2.15)] | NR | Age

NR = not reported; [ ] = NTP calculated risk estimates and CI.

^a^ Model 1: back-extrapolated missing air concentrations, holding 1972–1974 concentrations constant.

^b^ Model 2: back-extrapolated missing air concentrations, assuming two-fold higher concentrations than 1972–1974.

^c^ Model 3: back-extrapolated missing air concentrations by increasing (1937–1960) then decreasing (1960s–1970s) linear trends.

Jones (1994) reported a significantly increased risk of lung cancer mortality in antimony smelter workers compared with local mortality rates in England and Wales (standardized mortality ratio [SMR] = 1.55, 95% CI = 1.11 to 2.11; presented in Figure 4-1). The elevated risk of lung cancer mortality was maintained only for workers who joined prior to 1961 (SMR = 2.18, 95% CI = 1.51 to 3.04), and not for workers who joined during or after 1961 (SMR = 0.54, 95% CI = 0.20 to 1.20). No trend in lung cancer mortality was seen when stratifying by years as an antimony worker; however, an increased risk of lung cancer mortality was seen in antimony workers whose first exposure was more than 20 years ago. Changes in antimony smelting practices may help explain why the increased risk of lung cancer was only observed among workers hired at earlier time periods; however, follow-up (which is thought to be at least 20 years) may not be long enough for workers hired at later time periods. Considering the study included prevalent hires before the study enrollment date, it is possible the study missed antimony workers who may have been too sick to participate (i.e., HWSE).

Figure 4-1

Forest Plot of Effect Estimates of Lung Cancer Mortality (SMR or RR, 90% or 95% CI) in Metal Smelter Workers Exposed to Antimony in Available Cohort Studies

Study limitations that decrease this study’s sensitivity include a small-to-moderate number of exposed cases, no direct control of smoking or occupational co-exposures, and lack of individual-level exposure data. Occupational co-exposures to other lung cancer carcinogens at this smelter site include arsenic and arsenic compounds and possibly PAHs from blast furnaces. Given the reported variable use of arsenic and arsenic(III) trioxide in the smelting process over the study period, it is difficult to determine if arsenic exposure is confounding the relationship without more information. Jones (1994) noted smoking prevalence for all workers at the smelter site in 1961 was 72%. However, zircon sand millers in the same cohort had a lower lung cancer mortality risk than the referent population (SMR = 0.57, 95% CI = 0.18 to 1.33; 5 cases), suggesting that smoking alone may not account for all increased lung cancer mortality. Overall, the evidence for an association for exposure specific to antimony and lung cancer is inconclusive.

Schnorr et al. (1995) reported a lung cancer SMR of 1.39 (90% CI = 1.01 to 1.88) for white and Spanish-surnamed antimony smelter workers in the United States (28 exposed lung cancer cases), when compared with state ethnic-specific expected lung cancer deaths (presented in Figure 4-1). Longer employment duration increased the risk of lung cancer mortality for white and Spanish-surnamed men (test for trend = p < 0.005). When compared to the expected U.S. white male mortality rates, the risk of lung cancer mortality was not elevated in antimony smelter workers.

Several limitations may impact the interpretation of the risk estimates in this study (Schnorr et al. 1995), and they include the small-to-moderate number of exposed cases and lack of individual-level exposure data. Smoking and occupational co-exposures to other lung cancer carcinogens, such as arsenic and lead, were noted but not assessed in the study; however, bias from confounding was minimal. Spanish-surnamed workers were assumed to have substantially lower smoking and lung cancer mortality rates based on national trend data of Mexican Americans at the time. Composition of antimony ore and air sampling of arsenic were assessed at the smelter site. Authors noted the sourced ore generally contained <1% arsenic and lead, and 32% to 60% antimony. Furthermore, arsenic air concentrations were orders of magnitude lower than antimony concentrations: in 1975, mean airborne concentrations were 2 μg/m^3^ arsenic and 551 μg/m^3^ for 8-hour area samples; in 1976, mean airborne concentrations were 5 μg/m^3^ arsenic and 747 μg/m^3^ antimony for 8-hour personal (breathing zone) samples. Therefore, arsenic exposure is unlikely to fully account for the excess lung cancer mortality seen in this population. Overall, this study provides some evidence that antimony exposure is associated with an increased risk of lung cancer mortality, despite its limited sample size and lack of individual-level exposure data.

Jones et al. (2007) reported an increased risk for lung cancer mortality for workers with both unweighted and weighted cumulative exposure to ambient antimony in three different exposure scenarios, although significant risk estimates were seen only when exposure was weighted by attained age and time since exposure. In one exposure scenario (presented in Figure 4-1) where missing antimony air concentrations were assumed to be the mean of 1972 to 1974 concentrations, the calculated relative risk of lung cancer mortality from weighted cumulative antimony exposure was 3.25 (90% CI = 1.32 to 21.76). In an alternative exposure scenario where antimony air concentrations in 1937 were assumed to have been twice the mean measurements from 1972 to 1974, the calculated relative risk of lung cancer mortality from weighted cumulative antimony exposure was 5.26 (90% CI = 1.75 to 43.38). A dose-response relationship between cumulative exposure to antimony air concentrations and lung cancer mortality was seen for all three scenarios.

Limitations of the Jones et al. (2007) study included a small number of exposed cases and moderate concerns for potential biases (e.g., exposure misclassification and confounding). Although the study attempted to estimate missing antimony exposure measurements spanning over 30 years via data extrapolation, modeled exposure levels and timing of exposure may not represent true antimony concentrations and, thus, may not reflect true exposure for workers prior to 1972. Furthermore, the use of weighting factors (time since exposure and attained age) to modify cumulative exposure estimates are less than ideal as they were based on assumptions from a prior study of uranium workers (NRC 1999). It is unclear whether weighted or unweighted estimates are the best metric to evaluate the relationship.

The reported association between antimony exposure and lung cancer is potentially due to confounding from occupational arsenic and lead exposures. Based on air monitoring data at the smelter site, median estimated cumulative air lead concentrations (1.5 mg/m^3^-year) were higher than either arsenic (0.28 mg/m^3^-year) or antimony (0.37 mg/m^3^-year) from 1972 to 1991. Besides reporting increased lung cancer risk from antimony exposure, Jones et al. (2007) reported an increased risk of lung cancer mortality for weighted cumulative exposure to lead and arsenic, but not cadmium or polonium-210, in three exposure scenarios. A high level of correlation between lead, arsenic, and antimony air concentrations was seen at the smelter site, suggesting concurrent exposure. It is possible that arsenic, a known and potent lung carcinogen, is driving the observed incident lung cancer in this cohort. Since all three metals are highly correlated and offer similar slopes in their exposure-response relationships, the causality of one exposure over the other cannot be separated.

Although not controlled for in the analysis, smoking was likely not confounding the effect in Jones et al. (2007) given the large effect estimate and positive dose-response relationship observed. Furthermore, mortality from other non-cancer smoking-related diseases was not elevated in this cohort (Binks et al. 2005). Overall, this study provides inconclusive evidence that antimony exposure is positively associated with lung cancer mortality.

#### Integration of Evidence across Studies

Figure 4-1 displays the results of the three available studies in a forest plot. Risk estimates (SMR and RR) and confidence intervals (90% or 95% CI) show the relationship between metal smelter workers occupationally exposed to antimony and risk of lung cancer mortality.

All three studies found an elevated relative risk of lung cancer mortality in workers exposed to antimony in an occupational smelter setting, with a magnitude of effect of lung cancer mortality ranging from 1.39 to 5.23, based on both ever-exposure to antimony (Jones 1994; Schnorr et al. 1995) and a positive dose-response relationship (Jones et al. 2007). Workers from these cohorts were likely exposed to numerous antimony species, including antimony sulfides, antimony oxides, and other antimony compounds both from naturally occurring antimony ore and via the smelting process.

Human studies on antimony exposure and lung cancer were limited to three studies with a small number of antimony-exposed lung cancer cases. Unaccounted occupational co-exposures to lead and arsenic may be confounding these associations. Therefore, it is difficult to attribute lung cancer solely to occupational antimony exposure. Workers at all three smelter sites were exposed to a complex mixture of metals and other known lung cancer carcinogens. Concomitant exposure to compounds operating via mechanistic pathways lead to possible additive, more than additive, or other effects. Furthermore, limited information on smoking in each study population may have accounted for some, but not all, of the increased mortality attributed to antimony exposure.

### 4.3.2 Stomach Cancer

In 2017, there will be approximately 28,000 cases and 10,960 deaths of stomach cancer in the United States (SEER 2018). For stomach cancer from 1975 to 2014, age-adjusted incidence rates for men in the United States were 12.6 per 100,000 men (see Table 24.5 of Howlader et al. (2017)). Similar to lung cancer, stomach cancer has comparable low 5-year survival rate (30.3%) based on 2007 to 2013 SEER age-adjusted data (see Table 24.8 of Howlader et al. (2017)). Given the low survival for stomach cancer, mortality data may have similar utility as incidence data do.

Based on the study quality evaluation, two occupational cohort studies (Jones 1994; Schnorr et al. 1995) and one case-control study (Wingren and Axelson 1993) reporting on stomach cancer and antimony exposure were considered to be informative and were included in the cancer hazard assessment. The findings from individual studies are discussed below and presented in Table 4-3 and Appendix C, Table C-1, Table C-2, Table C-3, Table C-4, Table C-5, Table C-6. The two available occupational cohort studies of antimony and stomach cancer were a cohort of U.S. antimony smelter workers (Schnorr et al. 1995) and a cohort of U.K. tin smelters (Jones 1994). The available case-control study (Wingren and Axelson 1993) compared antimony exposure in cases of stomach cancer and local controls in a Sweden art glass-producing area.

#### Evidence from Individual Studies

The U.K. cohort of antimony smelter workers (Jones 1994) reported a non-statistically significant decrease in the risk of stomach cancer mortality in workers at an antimony smelter site compared with local mortality rates in England and Wales (SMR = 0.42, 95% CI = 0.05 to 1.51). As mentioned in Section 4.2, limitations of this study include a very low number of exposed cases, no direct control of smoking, and lack of individual-level exposure data. Evidence is inconclusive for the association of antimony exposure and stomach cancer mortality.

A non-statistically significant increase in the risk of stomach cancer mortality was seen in exposed workers from a U.S. antimony smelter, compared with both the national white male mortality rate (SMR = 1.49, 95% CI = 0.71 to 2.74; 10 cases) and state ethnic-specific male mortality rate (SMR = 1.24, 95% CI = 0.50 to 2.55; 7 cases) (Schnorr et al. 1995). As noted in Section 4.2, limitations of this study include a small number of stomach cancer deaths and lack of individual-level exposure data. The likelihood of confounding bias from smoking and lead exposure (both stomach cancer carcinogens) was minimal. Although lead exposure was concomitantly present, lead made up <1% of the antimony ore used at this plant. This study offers some evidence that antimony exposure increases risk of stomach cancer mortality.

A case-control study of Swedish art glass workers (Wingren and Axelson 1993) found an increased association of stomach cancer mortality in glass workers who died in parishes with low antimony consumption (odds ratio [OR] = 1.60, 90% CI = 0.90 to 2.60), but not in parishes with high antimony consumption (OR = 0.80, 90% CI = 0.30 to 2.00), when compared with the unexposed controls in these parishes. Since there was likely substantial exposure misclassification between the low and high consumption estimates due to imprecise assessment methods, in a post-hoc analysis NTP pooled both the low and high exposure for an ever-exposure risk estimate, which resulted in a weighted odds ratio of 1.36 which was not statistically significant (95% CI = 0.85 to 2.15). The highest risk of stomach cancer mortality was actually found in glass workers who died in parishes with no reported antimony consumption (OR = 2.00, 90% CI = 1.30 to 3.10), compared with unexposed controls in these parishes.

Major limitations in this study (Wingren and Axelson 1993) raise the potential for biased estimates and lowered study quality. The study did not report the number of cases or controls studied. Exposure to antimony was based on job title at death, which may be subject to misclassification. Furthermore, the characterization of exposure to antimony was not on an individual level but was based on antimony consumption patterns by glassworks. These antimony consumption patterns were solely based on a survey of metal consumption in the 1960s, and exposure at other periods was unknown.

Potential confounders that were not directly controlled for in Wingren and Axelson (1993) include smoking and occupational exposure to lead and asbestos. Although smoking prevalence was unknown, a previous study (Wingren and Axelson 1985) of the same study population reported a lower lung cancer mortality in the cohort compared with the Swedish mortality rate (SMR = 0.50, 95% CI = 0.32 to 0.74), which suggests that smoking was not associated with antimony exposure. Lead consumption was highly correlated with antimony consumption in the study (r = 0.76), and elevated lead air concentrations and detected lead on blowpipes used in the glass-working process were reported. Furthermore, an increased risk of stomach cancer mortality was found in glass workers who died in parishes with both low lead consumption (OR = 1.70, 90% CI = 1.00 to 2.80) and high lead consumption (OR = 1.50, 90% CI = 1.00 to 2.30), compared to unexposed controls. Therefore, the increased risk in stomach cancer mortality seen in workers who died in parishes with low antimony consumption may be subject to confounding bias by lead co-exposures. Asbestos was widely used in the art glass working process until the mid-1970s to handle warm glass products and in furnaces, leading to likely asbestos exposure among participants. Asbestos, however, is unlikely to be a major confounder given the lower rates of lung cancer deaths in the study population from a previous study on the same study population (Wingren and Axelson 1985). Overall, this study provides inconclusive evidence of antimony exposure and stomach cancer mortality.

##### Integration of Evidence Across Studies

The available studies do not indicate a consistent pattern of increased stomach cancer mortality associated with antimony exposure. In similar populations of antimony smelter workers, two studies offered conflicting results for antimony exposure and risk of stomach cancer mortality. The case-control study of a Swedish art glass region only showed a nonsignificant increased odds of stomach cancer mortality for cases who died in parishes with low antimony consumption, but not in parishes with high antimony consumption. Additionally, co-exposure to other stomach cancer carcinogens, including lead, and smoking, may be confounding the reported associations.

### 4.3.3 Other Types of Cancers

Available data are inadequate to evaluate other types of cancers in human studies of antimony exposure. Two cohort studies examined colon cancer mortality in relation to antimony exposure, but they reached conflicting conclusions. Schnorr et al. (1995) reported only two colon cancer cases in U.S. antimony smelter workers. The study found a significantly lower risk of colon cancer mortality in antimony-exposed workers (SMR = 0.12, 95% CI = 0.01 to 0.45) compared with U.S. white males. Wingren and Axelson (1993), on the contrary, reported an increased OR of 5.00 (90% CI = 2.60 to 9.60) for colon cancer in male glass workers who died in a parish where glassworks reported using a high level of antimony, compared with unexposed controls. Furthermore, an increasing trend of colon cancer risk was seen with greater consumption of antimony by parish. Although these trends may indicate an increased risk for colon cancer, lack of adequate individual-level exposure information and potential confounding by co-exposure to other metals limited the interpretation of these results.

Jones (1994) reported other malignant neoplasms in antimony smelter workers, but no cancer sites were specified. Schnorr et al. (1995) also reported increased risks of mortality in cancers in buccal cavity and pharynx, liver, biliary tract, and gall bladder, as well as cancers from unspecified sites in male antimony smelter workers, when compared with U.S. mortality rates and to state ethnic-specific rates. However, the available data are inadequate to evaluate these cancer sites given the lack of a priori hypotheses as noted by Schnorr et al. (1995) and no additional studies examining these specific endpoints.

A prospective mortality linkage study of National Health and Nutrition Examination Survey (NHANES) participants by Guo et al. (2016) saw an increased risk of death from malignant neoplasms when comparing the highest quartile of urinary antimony concentrations to the lowest quartile (fully adjusted hazard ratio [HR] = 1.20, 95% CI = 0.70 to 2.06). However, no trend was seen across quartiles (p value for trend test = 0.20). Furthermore, as noted in Section 4.1, all malignant neoplasms (i.e., all sites as one outcome) are insensitive for evaluating potential cancer hazards.

## 4.4 NTP’s Level-of-evidence Conclusion

The available human studies are inadequate to evaluate the relationship between antimony exposure and human cancer. The reported excess lung and stomach cancer deaths associated with occupational antimony exposure are potentially confounded by co-exposure to other lung and stomach cancer carcinogens.

The relevant data for evaluation of antimony exposure are two cohort studies of antimony smelter workers in the United Kingdom (Jones 1994) and the United States (Schnorr et al. 1995), a cohort study of tin smelter workers in the United Kingdom (Jones et al. 2007), and a case-control study of art glass workers in Sweden (Wingren and Axelson 1993).

For lung cancer, elevated mortality was seen in all studies of antimony-exposed smelter worker cohorts; however, it is not clear whether the increased risk was due to exposure to antimony. Results may be impacted due to non-differential exposure misclassification and confounding bias due to concurrent exposure from other metals.

An increased risk of stomach cancer was found in the U.S. antimony smelter cohort study (Schnorr et al. 1995) and the Swedish case-control study (Wingren and Axelson 1993), but not in the U.K. antimony smelter cohort study (Jones 1994).