# 1 Chemical Identification and Properties

This section provides information on the physical and chemical properties of antimony(III) trioxide (Sb_2_O_3_) and on antimony compounds with toxicological and other relevant information (Sections 3, 4, 5, and 6). As mentioned in the Introduction and Methods, toxicological information (Section 6) and information on properties for other antimony compounds (see below) may inform the cancer hazard evaluation of antimony(III) trioxide.

## 1.1 Properties of Antimony(III) Trioxide and Other Antimony Compounds

Antimony(III) trioxide exists as an odorless white powder or polymorphic crystals (HSDB 2013). It is slightly soluble in water, dilute sulfuric acid, dilute nitric acid, or dilute hydrochloric acid. It is soluble in solutions of alkali hydroxides or sulfides and in warm solutions of tartaric acid or of bitartrates. Figure 1-1 shows the chemical structure for antimony(III) trioxide and Table 1-1 presents its physical and chemical properties.

Figure 1-1

Structure for Antimony(III) Trioxide

Table 1-1 Physical and Chemical Properties for Antimony(III) Trioxide

Property | Information
Chemical formula | Sb_2_O_3_^a^
CAS No. | 1309-64-4^b^
InChi key | GHPGOEFPKIHBNM-UHFFFAOYSA-N^c^
Molecular weight | 291.5^a^
% Antimony by weight | 83.6
Antimony charge | +3^a^
Specific gravity, at 24°C | 5.9^c^
Melting point | 655°C^c^
Boiling point | 1,425°C^c^
Water solubility, at 22.2°C | [3.3 × 10^−4^] g/100 mL^d,e^
Vapor pressure, at 574°C | 1 mm Hg^c^

^a^ ChemIDplus (2017).

^b^ U.S. EPA (2017a).

^c^ PubChem (2017).

^d^ IPCS (2017).

^e^ Reported as 0.0033 g/L; brackets denote conversion of units.

Physical and chemical properties for other antimony compounds discussed in this monograph are listed in Table 1-2 together with their structures; the compounds listed are those with carcinogenicity (Sections 4 and 5), mechanistic (Section 6), or disposition (Section 3) data. In addition to elemental antimony (valence = 0), most antimony compounds have valences of either +3 (11 compounds) or +5 (6 compounds) although one compound with valence −3 is also included in the table. Compounds with +3 valence are likely to share more similarity with antimony(III) oxide but as discussed in Sections 2 and 3, interconversion between antimony(III) and antimony(V) occurs during manufacturing processes, in the environment, and in vivo. Both the +3 and +5 valence states include both inorganic antimony compounds, e.g., antimony(III) trisulfide and antimony(V) pentasulfide, and organic antimony compounds, primarily those used as anti-leishmanial drugs, such as sodium antimony 2,3-mesodimercaptosuccinate (the active ingredient in Astiban) and sodium stibogluconate(V) (the active ingredient in Pentostam).

Table 1-2 Physical and Chemical Properties for Metallic (Elemental) Antimony and Other Antimony Compounds with Carcinogenicity or Mechanistic Data

Name | CAS No. (InChI Key) | Formula | Chemical Structure | Molecular Weight (% Sb by Weight) | Density or Specific Gravity | Solubility in Water (g/100 mL), Descriptive Level^c^
Valence = 0
Antimony (elemental) | 7440-36-0^a^ (WATWJIUSRGPENY-UHFFFAOYSA-N^a^) | Sb^a^ | Sb | 121.8^a^ (100.0^a^) | 6.68^a, b^ | Insoluble^a^
Valence = −3
Stibine | 7803-52-3^a^ (OUULRIDHGPHMNQ-UHFFFAOYSA-N^a^) | SbH_3_^a^ | | 124.8^a^ (97.6a) | 2.26^a,d^ | [4.1 × 10-1]^a,e^ Slightly soluble
Valence = +3
Antimony acetate; acetic acid antimony (+3) salt | 6923-52-0^a^ (JVLRYPRBKSMEBF-UHFFFAOYSA-K^a^) | C_6_H_9_O_6_Sb^a^ | | 298.9^a^ (40.7^a^) | – | –
Antimony hydroxide | 39349-74-1^f^ (SZOADBKOANDULT-UHFFFAOYSA-K^a^) | H_3_O_3_Sb^a^ | | 172.8^a^ (70.5^a^) | – | –
Antimony potassium tartrate^g^ | 28300745^a^ (WBTCZEPSIIFINA-MSFWTACDSA-J^a^) | C_8_H_4_K_2_O_12_Sb_2_^g^ | | 667.8^a^ (36.5^a^) | 2.6^a^ | [8.3 × 10^0^]^a,h^ Soluble
Antimony tartrate^i^ | 12544-35-3^f^ (JFVMOLRNQCNLCHI-WZZCOQPSA-J^f^) | C_8_H_4_O_12_Sb_2_^f^ | | 535.6^f^ (45.5^f^) | – | [2.8 × 10^2^]^j^ Very soluble
Antimony trichloride | 10025-91-9^a^ (FAPDDOBMIUGHIN-UHFFFAOYSA-K^a^) | SbCl_3_^a^ | | 228.1^a^ (53.4^a^) | 3.14^a,k^ | [10 × 10^0^]^a,l^ Soluble
Sodium antimony(III) gluconate (antimony(III) sodium gluconate) | 12550-17-3^f^ (JEKOQEIHGHQVEI-ZBHRUSISSA-M^f^) | C_6_H_8_NaO_7_Sb^f^ | | 336.9^f^ (36.2^f^) | – | –
Sodium antimony 2,3-mesodimercaptosuccinate (active ingredient in Astiban) | 3064-61-7^a^ (AOGOCZMBIYQOFE-UHFFFAOYSA-B^a^) | C_12_H_6_Na_6_O_12_S_6_Sb_2_^a^ | | 916.0^a^ (26.6^a^) | – | –
Stibophen^m^ | 15489-16-4^f^ (ZDDUXABBRATYFS-UHFFFAOYSA-F^f^) | C_12_H_4_O_16_S_4_Sb•7H_2_O.5Na^f^ | | 895.2^f^ (13.6^f^) | – | –
Trimethylstibine | 594-10-5^a^ (PORFVJURJXKREL-UHFFFAOYSA-N^a^) | C_3_H_9_Sb^a^ | | 166.9^a^ (73.0^a^) | – | –
Triphenylstibine | 603-36-1^a^ (HVYVMSPIJIWUNA-UHFFFAOYSA-N^a^) | C_18_H_15_Sb^a^ | | 353.1^a^ (34.5^a^) | – | [4.3 × 10^−6^]^f,n^ Insoluble
Valence = +5
Antimony pentachloride | 7647-18-9^a^ (VMPVEPPRYRXYNP-UHFFFAOYSA-I^a^) | SbCl_5_^a^ | | 299.0^a^ (40.7^a^) | 2.35^a, k^ | –
Antimony pentasulfide | 1315-04-4^a^ (PPKVREKQVQREQD-UHFFFAOYSA-N^a^) | S_5_Sb_2_^a^ | | 403.8^a^ (60.3^a^) | – | [9.9 × 10^−6^]^o^ Insoluble
Antimony pentoxide | 1314-60-9^f^ (LJCFOYOSGPHIOO-UHFFFAOYSA-N^f^) | Sb_2_O_5_^f^ | | 323.5^f^ (75.3^f^) | – | [4.3 × 10^−6^]^p^ Insoluble
Sodium stibogluconate (active ingredient in Pentostam) | 16037-91-5^f^ (CUEDNFKBTFCOSV-UZVLBLASSA-L^f^) | C_12_H_20_O_17_Sb_2._3Na•9H_2_O^f^ | | 908.9^f^ (26.8^f^) | – | –
Meglumine antimoniate | 133-51-7^a^ (XOGYVDXPYVPAAQ-SESJOKTNSA-M^a^) | C_7_H_18_NO_8_Sb^a^ | | 366.0^a^ (33.3^a^) | – | –
Potassium hexahydroxy antimonate | 12208-13-8^q^ (IAYJQRROUBIPRX-UHFFFAOYSA-H^f^) | H_6_KO_6_Sb^q^ | | 262.9^q^ (46.3^q^) | – | –

– = No data found; CAS = Chemical Abstracts Service; InChI = IUPAC International Chemical Identifier.

^a^ PubChem (2017).

^b^ At 77°F.

^c^ Descriptive levels are converted from solubility in water (Solubility of Things 2018).

^d^ At −25°C.

^e^ Reported as 4.1 g/L at 0°C in water. Brackets denote unit conversion.

^f^ ChemIDplus (2017).

^g^ Formula and structure shown are for anhydrous form of antimony potassium tartrate.

^h^ Reported as 83,000 mg/L at 20°C. Brackets denote unit conversion.

^i^ Antimony tartrate ion. Felicetti et al. (1974a) reported starting solution as 124Sb-tartrate complex.

^j^ EPA CompTox Chemistry Dashboard (2017b). Reported as mean of 5.55 mol/L. Brackets denote unit conversion.

^k^ At 68°F.

^l^ At 25°C.

^m^ The anhydrous form of Stibophen is C12H4Na5O16S4Sb (CAS number = 23940-36-5, molecular weight = 769.1 g/mol).

^n^ Reported as 0.043 mg/L at 25°C. Brackets denote unit conversion. Accessed 11/29/2017.

^o^ EPA CompTox Chemistry Dashboard (2017b). Reported as 2.46 × 10-7 mol/L. Brackets denote unit conversion.

^p^ EPA CompTox Chemistry Dashboard (2017b). Reported as 1.32 × 10-7 mol/L by EpiSuite (2017). Brackets denote unit conversion.

^q^ ChemSpider (2017).

Solubilization of some water-insoluble compounds may be enhanced in biological fluids at low pH and in the presence of binding proteins (IARC 2006), and this information may provide better understanding of potential absorption of an antimony compound than solubility in water. Because in vivo bioavailability testing can be cost prohibitive and time consuming, solubility of compounds in artificial fluids (i.e., bioaccessibility) can be estimated using synthetic equivalents of gastric fluid (for ingestion exposure), interstitial and lysosomal fluids (for inhalation exposure), perspiration fluids (for dermal exposure), and human blood serum (for transport within the body). The solubility of antimony(III) trioxide and other antimony compounds in these different fluids, which have pH ranging from 1.6 for gastric fluid to 7.4 for lung interstitial fluid and human blood serum are listed in Table 1-3. European Union Registration, Evaluation and Authorisation of CHemicals (REACH) data for bioaccessibility for antimony(III) trioxide, antimony(V) pentoxide, and antimony(III) sulfide in simulated human fluids is expressed as percent solubility in simulated human fluids at various pH values (ECHA 2017). For these three antimony compounds, in fluids simulating physiologic pH, bioaccessibility after 24 hours of exposure was highest for antimony(III) trioxide and lowest for antimony sulfide, with antimony pentoxide occupying an intermediate position. Antimony(III) trioxide had the highest percent solubility in artificial alveolar lysosomal fluid (pH = 4.5), which may be representative of the lung tissue contacted by inhaled antimony(III) trioxide (see Section 2) (ECHA 2017). Intermediate values were reported for artificial sweat (pH = 6.5), interstitial fluid within the deep lung (pH = 7.4), and human blood serum (pH = 7.4). The lowest value reported was for artificial gastric fluid (pH = 1.6).

Table 1-3 Bioaccessibility of Antimony(III) Trioxide and Other Antimony Compounds

Antimony Compound | Percent (%) Solubility in Simulated Human Fluid after 24 Hours of Exposure
Antimony Compound | Gamble’s Solution^a^ (pH = 7.4) | Phosphate-buffered Saline^b^ (pH = 7.4) | Artificial Sweat^c^ (pH = 6.5) | Artificial Lysosomal Fluid^d^ (pH = 4.5) | Artificial Gastric Fluid^e^ (pH = 1.6)
Antimony(III) trioxide | 56.7 | 41.5 | 60.8 | 81.7 | 13.6
Antimony(V) pentoxide | 32.5 | 29.2 | 60.8 | 71.4 | 94.3
Antimony(III) sulfide | 3.9 | 8.5 | 3.6 | 5.1 | 4

Source: ECHA (2017).

^a^ Gamble’s solution mimics interstitial fluid within the deep lung under normal health conditions.

^b^ Phosphate-buffered saline mimics the ionic strength of human blood serum.

^c^ Artificial sweat mimics hypo-osmolar fluid excreted upon sweating.

^d^ Artificial lysosomal fluid mimics intracellular conditions in lung cells during phagocytosis.

^e^ Artificial gastric fluid mimics stomach acid.

## 1.2 Antimony Speciation and Variability of Valence

The form of antimony (i.e., its speciation) affects its toxicity, mobility, and transformation in the environment, and antimony speciation depends on pH and redox potential (Herath et al. 2017). Similar to many other metallic elements, antimony toxicity is thought to be exerted through its ions (EU 2008), and ions of antimony are capable of performing redox reactions in biological systems (Beyersmann and Hartwig 2008). In general, antimony(III) species have been reported to be more toxic than antimony(V) species (Filella et al. 2002a; Herath et al. 2017); however, the European Union (2008) noted that there is no evidence to support a firm conclusion on toxicity differences for the two valences, and ORoC was also unable to identify data showing a clear difference in toxicity based on valence.

Elemental antimony exists in four primary oxidation states; −3, 0, +3, and +5; Sb(III) (trivalent form) and Sb(V) (pentavalent form) are the most common in environmental, biological, and geochemical systems. Thermodynamic equilibrium calculations indicate that antimony(V) predominates in oxic systems, and antimony(III) predominates in anoxic systems. However, antimony(III) concentrations at higher than calculation-predicted values have been detected in oxic systems; similarly, higher than calculation-predicted antimony(V) concentrations have been detected in anoxic systems (Filella et al. 2002a). Both trivalent (III) and pentavalent (V) antimony ions hydrolyze readily. When any form of antimony dissolves in water, it exists as the hydroxide forms, Sb(OH)_3_ (uncharged) or Sb(OH)_6_^−^ (charged) (Herath et al. 2017). Antimony(III) is present as the neutral species Sb(OH)_3_ (or H_3_SbO_3_) for pH values from 2 to approximately 10 (Krupka and Serne 2002) and antimony(V) is present as the anion Sb(OH)_6_^−^ (or H_2_SbO_4_^−^) for pH values from 2.7 to 10.4 (EU 2008; Herath et al. 2017). As shown in Figure 1-2, these forms are the major ones at physiologic pH around 7.4. Figure 1- 2 also illustrates antimony speciation for antimony(III) and antimony(V) species over a pH range of 0 to 12. Positively charged species are reported to generally exist only under very acidic conditions (i.e., pH < 2) (Herath et al. 2017).

Figure 1-2

Antimony Speciation for Antimony(III) and Antimony(V) Species over a Range of pH Values

Sb(OH)_2_^+^ = dihydroxoantimony (III); Sb(OH)_3_/H_3_SbO_3_ = trihydroxy antimony (III)/antimonous acid (III); H_2_SbO_3_- = dissociated form of Sb_2_O_3_ (III); Sb(OH)_4_^-^ = tetrahydroxoantimony (III), dissociated form of Sb_2_O_3_; SbO_2_^+^ = cation (V); H_3_SbO_4_ = antimonic acid (V); H_2_SbO_4_^-^ = dihydrogen antimonate (V); Sb(OH)_6_^-^ = antimonate ion (V), hexahydroxoantimonate.

Source: Adapted from Herath et al. (2017).

The evidence for formation of these hydroxide forms in cellular or extracellular fluids is limited; however, the presence of Sb(III) in oxic water at higher than predicted levels has been proposed to be related to the presence of organic matter, particularly organic acids that also occur in plasma, such as citric acid, pyruvic acid, and fumaric acid (Filella et al. 2002a; 2002b).

Inorganic forms generally are found more often than organic forms in many environmental systems (EU 2008; Herath et al. 2017). However, antimony can form organic compounds via biological methylation (i.e., the chemical combination of methyl groups with metals or metalloids through the action of a living organism such as bacteria, fungi, or plants) (Filella et al. 2007). Evidence for in vivo methylation of antimony in mammals is limited (see Section 3).

## 1.3 Detection of Antimony and Antimonial Species

Measurements in both environmental and biological samples (Table 1-4) can include total antimony, the oxidation state of antimony, and methylated species (Belzile et al. 2011).

Table 1-4 Methods for Detection of Antimony and Antimonial Species in Environmental and Biological Samples

Method | Antimony (Sb) Forms Measured: Environmental | Antimony Forms Measured: Biological | Reference(s)
Atomic absorption spectrometry (AAS) with either flame or graphite furnace | Total Sb | – | ATSDR (2017)
Inductively coupled plasma-atomic emission spectroscopy (ICP-AES) | Total Sb | Total Sb in blood, tissue, hair, and others | ATSDR (2017)
Hydride generation-atomic absorption spectrometry (HG-AAS) | Sb(III) and Sb(V) species in river water | – | ATSDR (2017); Zheng et al. (2006)
Liquid chromatography-hydride generation-atomic fluorescence spectrometry (LC-HG-AFS) | Sb(III) and Sb(V) in tap water and river water | – | ATSDR (2017); Vinas et al. (2006)
Ion chromatography with inductively coupled plasma-atomic emission spectrometry (IC-ICP-AES) and mass spectrometry (ICP-MS) | Sb(III) and Sb(V) and in surface water samples and soil extracts | Total Sb in urine, serum, blood, liver, and lung tissue; Sb(III) and Sb(V) in plant tissues (with HPLC separation) | Müller et al. (2009); Ulrich (1998)
High-performance liquid chromatography-hydride generation-atomic fluorescence spectrometry (HPLC-HG-AFS) | Sb(III), Sb(V) and total antimony in road dust and airborne particulate matter | Sb(III) and Sb(V) in human urine, marine algae, and mollusks | ATSDR (2017); Quiroz et al. (2011)
High-performance liquid chromatography-ultraviolet-hydride generation-atomic fluorescence spectrometry (HPLC-UV-HG-AFS) | – | Sb(III) and Sb(V) in marine algae and mollusks | ATSDR (2017); De Gregori et al. (2007)

## 1.4 Summary

Elemental antimony is a metalloid that exists in four primary oxidation states: −3, 0, +3, and +5. The most common forms in environmental, biological, and geochemical systems are Sb(III) (the trivalent form) and Sb(V) (the pentavalent form). Antimony speciation can affect its toxicity, mobility, and transformation in the environment. Detection of antimony species depends on chromatographic separation of Sb(III) from Sb(V) followed by determination of elemental antimony by methods such as atomic absorption spectrometry after destruction of the chemical compound at high temperatures or conversion to the hydride.

Antimony(III) trioxide is the oxide of trivalent (+3) antimony that exists as an odorless white powder or polymorphic crystals (HSDB 2013). It is only slightly soluble in water, but it is bioaccessible in artificial body fluids, especially lysosomal fluid of lung cells where more than 80% dissolves in 24 hours. In solution, antimony(III) trioxide exists primarily as the uncharged hydroxide form, Sb(OH)_3_.