# Peer Review

Peer review of the Draft RoC Monograph on Antimony Trioxide was conducted by an ad hoc expert panel at a public meeting held on January 24, 2018, in the Rodbell Auditorium at the National Institute of Environmental Health Sciences, David P. Rall Building, Research Triangle Park, NC (see https://ntp.niehs.nih.gov/go/38854 for materials, minutes, and panel recommendations from meeting). The selection of panel members and conduct of the peer review were performed in accordance with the Federal Advisory Committee Act and Federal policies and regulations. The panel members served as independent scientists, not as representatives of any institution, company, or governmental agency.

The charge to the Peer-Review Panel was as follows:

1. Comment on whether the Draft RoC Monograph on Antimony Trioxide is technically correct, clearly stated, and objectively presented.
2. Provide opinion on whether there is currently or was in the past significant human exposure to antimony trioxide.

The Panel was asked to vote on the following questions:

1. Whether the scientific evidence supports NTP’s conclusions on the level of evidence for carcinogenicity from cancer studies in animals for antimony trioxide.
2. Whether the scientific evidence supports NTP’s preliminary policy decision on the listing status of antimony trioxide.

The monograph has been revised based on NTP’s review of the Panel’s peer-review comments. The Peer-Review Panel Report, which captures the Panel recommendations for listing status of antimony trioxide in the RoC and their scientific comments, are available on the Peer-Review Meeting webpage for antimony trioxide (https://ntp.niehs.nih.gov/go/38854).

## Peer Reviewers

- Rebecca Fry, Ph.D. (Chair)
  Professor, Department of Environmental Sciences and Engineering
  Director, UNC Superfund Research Program
  Director, Institute for Environmental Health Solutions
  Gillings School of Global Public Health
  University of North Carolina at Chapel Hill
  Chapel Hill, North Carolina, USA
- Richard Peterson II, D.V.M., Ph.D., DACVP
  Senior Investigative Pathologist
  Global Preclinical Safety
  Investigative Toxicology and Pathology
  AbbVie
  Libertyville, Illinois, USA
- Elaine Symanski, Ph.D.
  Professor and Chair, Southwest Center for Occupational and Environmental Health
  Department of Epidemiology, Human Genetics and Environmental Sciences
  School of Public Health
  The University of Texas Health Science Center at Houston
  Houston, Texas, USA
- Michael Waalkes, Ph.D.
  Retired, Senior Advisor
  Division of the National Toxicology Program
  National Institute of Environmental Health Sciences
  Raleigh, North Carolina, USA
- Elizabeth Ward, Ph.D.
  Retired, Senior Vice President for Intramural Research
  American Cancer Society
  Asheville, North Carolina, USA
- John Wise, Sr., Ph.D.
  Professor, Department of Pharmacology and Toxicology
  University of Louisville
  Louisville, Kentucky, USA
- Hao Zhu, Ph.D.
  Associate Professor, Department of Chemistry
  The Rutgers Center for Computational and Integrative Biology
  Rutgers University-Camden
  Camden, New Jersey, USA