# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Responsible for executing and coordination of project activities, including conception, design, planning, conduct, and technical review of cancer hazard
  H.S. Amy Wang, Ph.D.
  Ruth M. Lunn, Dr.P.H.
- RoC Evaluation Team
  Contributed to design, conduct, technical review, and interpretation and integration of studies in the evaluation
  Andrew D. Ewens, Ph.D., ILS, Inc., Research Triangle Park, North Carolina, USA
  Sanford C. Garner, Ph.D., ILS, Inc., Research Triangle Park, North Carolina, USA
  Alton F. Peters, M.S. ILS, Inc., Research Triangle Park, North Carolina, USA
  Suril S. Mehta, M.P.H., Division of the National Toxicology Program (DNTP), National Institute of Environmental Health Sciences (NIEHS)
  Joanne Trgovcich, Ph.D., ICF, Durham, North Carolina, USA
  Kristine L. Witt, M.S., Division of the National Toxicology Program (DNTP), National Institute of Environmental Health Sciences (NIEHS)