# Glossary

6-4 Photoproducts: DNA photoproducts with (6-4) pyrimidine-pyrimidone adducts.
Agranulocyte: A leukocyte (white blood cell) lacking apparent cytoplasmic granules when viewed under light microscopy (in contrast to granulocytes).
Anoxic: A condition or an environment that lacks oxygen, as anoxic water which is devoid of oxygen.
Apoptosis: Cell deletion by fragmentation into membrane-bound particles, which are phagocytosed by other cells.
Attrition bias: Systematic differences between comparison groups in withdrawals or exclusions of participants from the results of a study.
Boiling point: The boiling point of the anhydrous substance at atmospheric pressure (101.3 kPa) unless a different pressure is stated. If the substance decomposes below or at the boiling point, this is noted. The temperature is rounded off to the nearest °C.
Chemical Data Reporting Rule: Chemical Data Reporting (CDR) is the new name for Inventory Update Reporting (IUR). The purpose of Chemical Data Reporting is to collect quality screening-level, exposure-related information on chemical substances and to make that information available for use by the U.S. Environmental Protection Agency (EPA) and, to the extent possible, to the public. The IUR/CDR data are used to support risk screening, assessment, priority setting and management activities and constitute the most comprehensive source of basic screening-level, exposure-related information on chemicals available to EPA. The required frequency of reporting currently is once every 4 years.
Clastogenesis: The process resulting in additions, deletions, or rearrangements of parts of the chromosomes that are detectable by light microscopy.
Comet assay: Single cell gel electrophoresis for assessment of DNA damage in presumptive target tissues.
Diapedesis: The movement of blood cells, particularly leukocytes, from the blood across blood vessel walls into tissues.
Disposition: The description of absorption, distribution, metabolism, and excretion of a chemical in the body.
Enterohepatic circulation (enterohepatic cycling, enterohepatic recycling): Circulation of substances such as bile salts that are absorbed from the intestine and carried to the liver, where they are secreted into the bile and again enter the intestine.
FDA Good Laboratory Practice Regulations: A quality system codified by the U.S. Food and Drug Administration that prescribes operating procedures for conducting nonclinical laboratory studies that support or are intended to support applications for research or marketing permits for products regulated by the Food and Drug Administration.
Feret’s (or Feret) diameter: A measure used for analysis of irregular particle sizes that consists of the average of the perpendicular distances between two parallel planes touching each particle on opposite sides.
Fining agent: A chemical compound added to glass melts to remove bubbles.
Fire retardant: A liquid, solid, or gas that tends to inhibit combustion when applied on, mixed in, or combined with combustible materials.
Fisher’s exact test: The test for association in a two-by-two table that is based on the exact hypergeometric distribution of the frequencies within the table.
Follow-up: Observation over a period of time of a person, group, or initially defined population whose appropriate characteristics have been assessed to observe changes in health status or health-related variables.
Granulocyte: A type of white blood cell that has small granules, which contain proteins. The specific types of granulocytes are neutrophils, eosinophils, and basophils.
Healthy worker survival effect: A continuing selection process such that those who remain employed tend to be healthier than those who leave employment.
Healthy worker survivor effect: The selection process by which workers affected by their occupational exposure terminate prematurely their working life or transfer from higher to lesser exposed jobs, generally leading to under-estimation of risks and dose-response estimation. The healthy worker survivor effect is most prominent in cross sectional studies of disease prevalence and exposure.
Hypercytokinemia: A potentially fatal elevated release of inflammatory mediators in response to stimulation of T cells and macrophages by pathogens and immune insults.
Hypogeusia: A partial loss of the ability to taste.
Hyposmia: A partial loss of the ability to perceive smells.
In silico: An expression used to mean “performed on computer or via computer simulation.”
InChI key: A 27-character compacted version of the InChI (IUPAC [International Union of Pure and Applied Chemistry] International Chemical Identifier) intended for Internet and database searching and indexing.
Leishmaniasis: A parasitic disease that is found in parts of the tropics, subtropics, and southern Europe caused by infection with Leishmania parasites, which are spread by the bite of infected sand flies. The most common forms of leishmaniasis in people are cutaneous leishmaniasis, which causes skin sores, and visceral leishmaniasis, which affects several internal organs (usually spleen, liver, and bone marrow).
Loss of heterozygosity: If there is one normal and one abnormal allele at a particular locus, as might be seen in an inherited autosomal dominant cancer susceptibility disorder, loss of the normal allele produces a locus with no normal function. When the loss of heterozygosity involves the normal allele, it creates a cell that is more likely to show malignant growth if the altered gene is a tumor suppressor gene.
Melting point: The melting point of the substance at atmospheric pressure (101.3 kPa). When there is a significant difference between the melting point and the freezing point, a range is given. In case of hydrated substances (i.e., those with crystal water), the apparent melting point is given. If the substance decomposes at or below its melting point, this is noted. The temperature is rounded off to the nearest °C.
Metabolic activation: The chemical alteration of an exogenous substance by or in a biological system. The alteration may inactivate the compound, or it may result in the production of an active metabolite of an inactive parent compound.
Metalloid: A chemical element that exhibits some properties of metals and some of nonmetals.
Metaplasia: A change of cells to a form that does not normally occur in the tissue in which it is found.
Micronuclei: Small nuclei separate from, and additional to, the main nucleus of a cell, produced during the telophase of mitosis or meiosis by lagging chromosomes or chromosome fragments derived from spontaneous or experimentally induced chromosomal structural changes.
Miscible: A physical characteristic of a liquid that forms one liquid phase with another liquid (e.g., water) when they are mixed in any proportion.
Molecular weight: The molecular weight of a substance is the weight in atomic mass units of all the atoms in a given formula. The value is rounded to the nearest tenth.
Mucociliary transport: The process by which cilia move a thin film of mucus from the upper and lower respiratory tracts towards the digestive tract. Particles of dust and microorganisms are trapped on the mucus and thereby removed from the respiratory tract.
Mutations: A change in the structure of a gene, resulting from the alteration of single base units in DNA, or the deletion, insertion, or rearrangement of larger sections of genes or chromosomes. The genetic variant can be transmitted to subsequent generations.
National Health and Nutrition Examination Survey: A program of studies designed to assess the health and nutritional status of adults and children in the United States. The survey is unique in that it combines interviews and physical examinations.
Natural killer cells: A type of white blood cell that contains granules with enzymes that can kill tumor cells or microbial cells. Also called large granular lymphocytes.
Non-differential exposure misclassification: The probability of erroneous classification of an exposed individual into a category other than that to which they should be assigned is the same in all study groups.
Nonferrous: Not containing, including, or relating to iron.
Normochromatic erythrocyte: A mature erythrocyte that lacks ribosomes and can be distinguished from immature, polychromatic erythrocytes by stains selective for RNA.
Nrf2: A protein that controls how certain genes are expressed. These genes help protect the cell from damage caused by free radicals (unstable molecules made during normal cell metabolism). Also called NFE2L2 and nuclear factor (erythroid-derived 2)-like 2.
Octanol/water partition coefficient (log Kow): A measure of the equilibrium concentration of a compound between octanol and water.
Opacifier: A chemical used to make a solution or substance more opaque.
Oxic: Of a process or environment in which oxygen is involved or present.
Personal breathing zone: A sampling area as close as practical to an employee’s nose and mouth, (i.e., in a hemisphere forward of the shoulders within a radius of approximately 9 inches) so that it does not interfere with work performance or safety of the employee.
Plate incorporation: A commonly used procedure for performing a bacterial reverse mutation test. Suspensions of bacterial cells are exposed to the test substance in the presence and in the absence of an exogenous metabolic activation system. In the plate-incorporation method, these suspensions are mixed with an overlay agar and plated immediately onto minimal medium. After 2 or 3 days of incubation, revertant colonies are counted and compared with the number of spontaneous revertant colonies on solvent control plates.
Poly-3 trend test: A survival-adjusted statistical test that takes survival differences into account by modifying the denominator in the numerical (quantal) estimate of lesion incidence to reflect more closely the total number of animal years at risk.
Polychromatic erythrocyte: A newly formed erythrocyte (reticulocyte) containing RNA.
Primary mineral: In an igneous rock, any mineral that is formed during the original solidification (i.e., crystallization) of the rock. Primary minerals include both the essential minerals used to assign a classification name to the rock and the accessory minerals present in lesser abundance.
Proto-oncogene: A gene involved in normal cell growth. Mutations (changes) in a proto-oncogene may cause it to become an oncogene, which can cause the growth of cancer cells.
P_trend_: Level of statistical significance of a change over time in a group selected to represent a larger population.
QUOSA: A collection of scientific literature management software and services for researchers and information professionals in the life sciences and related scientific and medical areas designed to retrieve, organize, and analyze full-text articles and documents.
Reticuloendothelial cells: Cells with the ability to take up inert particles and vital dyes, e.g., macrophages, macrophage precursors, specialized endothelial cells lining the liver sinusoids, spleen, and bone marrow, and reticular cells of lymphatic tissue and bone marrow (fibroblasts).
Schistosomiasis: A disease caused by parasites (genus Schistosoma) that enter humans by attaching to the skin, penetrating it, and then migrating through the venous system to the portal veins where the parasites produce eggs and eventually, the symptoms of acute or chronic disease (for example, fever, abdominal discomfort, blood in stools).
Secondary mineral: A mineral formed through processes such as weathering and hydrothermal alteration (at a later time in contrast to primary minerals which form during the original solidification of the rock).
Selection bias: An error in choosing the individuals or groups to take part in a study. Ideally, the subjects in a study should be very similar to one another and to the larger population from which they are drawn (for example, all individuals with the same disease or condition). If there are important differences, the results of the study may not be valid.
Sister chromatid exchange: The exchange during mitosis of homologous genetic material between sister chromatids; increased as a result of inordinate chromosomal fragility due to genetic or environmental factors.
Solubility: The ability of a substance to dissolve in another substance and form a solution. The Report on Carcinogens uses the following definitions (and concentration ranges) for degrees of solubility: (1) miscible (see definition), (2) freely soluble-capable of being dissolved in a specified solvent to a high degree (>1,000 g/L), (3) soluble-capable of being dissolved in a specified solvent (10–1,000 g/L), (4) slightly soluble-capable of being dissolved in a specified solvent to a limited degree (1–10 g/L), and (5) practically insoluble-incapable of dissolving to any significant extent in a specified solvent (<1 g/L).
Specific gravity: The ratio of the density of a material to the density of a standard material, such as water at a specific temperature; when two temperatures are specified, the first is the temperature of the material and the second is the temperature of water.
Spot test: Qualitative assay in which a small amount of test chemical is added directly to a selective agar medium plate seeded with the test organism, e.g., Salmonella. As the chemical diffuses into the agar, a concentration gradient is formed. A mutagenic chemical will give rise to a ring of revertant colonies surrounding the area where the chemical was applied; if the chemical is toxic, a zone of growth inhibition will also be observed.
T90: Additional exposure time used in sub-chronic and chronic inhalation studies in experimental animals; the time required to achieve 90% of the target concentration after the beginning of vapor generation.
Time-weighted average: The average exposure concentration of a chemical measured over a period of time (not an instantaneous concentration).
Toxicokinetics: The determination and quantification of the time course of absorption, distribution, biotransformation, and excretion of a chemical in the body.
Transcriptomics: The study of all RNA transcripts of a cell, tissue, or organism (i.e., the transcriptome) to determine how the transcriptome, and hence pattern of gene expression, changes with respect to various factors, such as type of tissue, stage of development, hormones, drugs, or disease.
Transitions: DNA nucleotide substitution mutation in which a purine base is substituted for another purine base (adenine → guanine or guanine → adenine) or a pyrimidine base for another pyrimidine base (cytosine → thymine or thymine → cytosine).
Vapor pressure: The pressure of the vapor over a liquid (and some solids) at equilibrium, usually expressed as mm Hg at a specific temperature.