# Units of Measurement

Area
  cm^2^: square centimeter

Concentration
  g/L: grams per liter
  mg/kg b.w.: milligrams per kilogram body weight
  mg/L: milligrams per liter
  mg/m^3^: milligrams per cubic meter
  mg%: milligram percent (equivalent to milligrams per deciliter)
  mol/L: moles per liter
  ng/g: nanograms per gram
  ppm: parts per million
  μM: micromolar
  μmol/L: micromoles per liter
  μg/g: micrograms per gram
  μg/kg: micrograms per kilogram
  μg/L: micrograms per liter
  μg/m^3^: micrograms per cubic meter

Length
  ft: feet
  in: inch

Mass/Weight
  kg: kilogram
  lb: pound
  mg: milligram
  mol: mole
  ng: nanogram
  μg: microgram

Temperature
  °C: degrees Celsius

Volume
  dL: deciliter
  L: liter
  m^3^: cubic meter
  mL: milliliter