# Abbreviations

  AAS: atomic absorption spectrometry
  ADME: absorption, distribution, metabolism, and excretion
  ATG: Attagene
  ATM: ataxia-telangiectasia mutated kinase
  avg: average
  b.w.: body weight
  BDL: below detection limit
  BPDE: benzo[a]pyrene diol epoxide
  BPDE-DNA adducts: DNA adducts induced by (+)-anti-benzo[a]pyrene diol epoxide
  BRCA1: breast cancer type 1 (protein)
  BSC: NTP Board of Scientific Counselors
  BSO: dl-buthionine-[S,R]-sulfoximine
  CCRF-CEM: name of a cell line from acute lymphoblastic leukemia cells
  CDC: Centers for Disease Control and Prevention
  CI: confidence interval
  conc. (Conc.): concentration
  CPDs: cyclobutane pyrimidine dimers
  CSF2: colony-stimulating factor 2
  dGTP: deoxyguanosine triphosphate
  DNA: deoxyribonucleinc acid
  DSB(s): double-strand DNA break(s)
  EC50: half maximal effective concentration
  Egfr: epidermal growth factor receptor (mouse and rat gene)
  EGFR: epidermal growth factor receptor (human gene)
  EGFR: epidermal growth factor receptor (protein)
  ELISA: enzyme-linked immunosorbent assay
  EPA: U.S. Environmental Protection Agency
  EU: European Union
  F: female(s)
  FDA: U.S. Food and Drug Administration
  FISH: fluorescence in situ hybridization
  FPG: formamidopyrimidine-DNA glycosylase
  GI: gastrointestinal
  GLP: Good Laboratory Practice
  GSD: geometric standard deviation
  GSH: glutathione
  GSSG: glutathione disulfide
  GST: glutathione S-transferase
  GTP: guanosine triphosphate
  HBr: hydrogen bromide
  HCl: hydrogen chloride
  HepG2: a cell line from human liver carcinoma
  HG-AAS: hydride generation-atomic absorption spectrometry
  HHS: Department of Health and Human Services
  HIC: highest ineffective concentration
  HPLC-HG-AFS: high-performance liquid chromatography-hydride generation-atomic fluorescence spectrometry
  HPLC-UV-HG-AFS: high-performance liquid chromatography-ultraviolet-hydride generation-atomic fluorescence spectrometry
  hr: hour(s)
  HR: hazard ratio
  HTS: USITC harmonized tariff schedule
  HWSE: healthy worker survival effect
  i.m.: intramuscular(ly)
  i.p.: intraperitoneal(ly)
  i.v.: intravenous(ly)
  IC-ICP-AES: ion chromatography with inductively coupled plasma-atomic emission spectrometry
  ICD: International Classification of Diseases
  ICD-8: ICD Revision 8
  ICD-9: ICD Revision 9
  ICF: ICF Incorporated, LLC
  ICP-AES: Inductively coupled plasma-atomic emission spectroscopy
  ICP-MS: mass spectrometry
  iCSS: interactive Chemical Safety for Sustainability (dashboard)
  ILS: Integrated Laboratory Systems, Inc
  JEM: job-exposure matrix
  K-562: chronic myelogenous leukemia cells
  LC-HG-AFS: liquid chromatography-hydride generation-atomic fluorescence spectrometry
  LEC: lowest effective concentration
  LOUCY: T cell acute lymphoblastic leukemia cells
  M: male(s)
  MMAD: mass median aerodynamic diameter
  MMP: mitochondrial membrane potential
  mo: month(s)
  MPPD: multiple path particle deposition (model)
  N: number (e.g., total number of animals tested in a group)
  n/N: number of animals with neoplasms divided by the total number of animals tested in that group
  NAICS: North American Industry Classification System
  NAWQA: National Water-Quality Assessment
  NB4: acute promyelocytic leukemia cells
  NB4-M-AsR3: arsenic-resistant APL cells derived in Miller laboratory
  NC: negative control
  NCBI GEO: National Center for Biotechnology Information Gene Expression Omnibus
  NCTR: National Center for Toxicological Research
  ND: not determined
  Neg: negative
  NER: nucleotide excision repair
  NHANES: National Health and Nutrition Examination Survey
  NHEJ: non-homologous end joining
  NIEHS: National Institute of Environmental Health Sciences
  NIH: National Institutes of Health
  NIOSH: National Institute for Occupational Safety and Health
  NOES: National Occupational Exposure Survey
  NOS: not otherwise specified
  NR: not reported
  NTP: National Toxicology Program
  NVS: NovaScreen
  OR: odds ratio
  ORoC: Office of the Report on Carcinogens
  OSHA: Occupational Safety and Health Administration
  PAHs: polycyclic aromatic hydrocarbons
  PC: positive control
  PET: polyethylene terephthalate
  pH: potential of hydrogen (a logarithmic scale used to specify the acidity or basicity of an aqueous solution)
  PHS: Public Health Service
  Pos: positive
  PVC: polyvinyl chloride
  r: correlation coefficient
  R: rat(s)
  REACH: European Union Registration, Evaluation and Authorisation of CHemicals
  RNA: ribonucleic acid
  RoC: Report on Carcinogens
  ROS: reactive oxygen species
  RR: relative risk
  s.c.: subcutaneous(ly)
  SCE: sister chromatid exchange
  SD: standard deviation
  SE: standard error
  SEER: Surveillance, Epidemiology, and End Results (program)
  SIC: standard industrial classification
  SIK: a cell line from spontaneously immortalized human keratinocytes
  SMR: standardized mortality ratio
  std dev: (geometric) standard deviation
  TK: toxicokinetics
  TLV: threshold limit value
  TREM1: triggering receptor expressed on myeloid cells 1
  TRI: Toxics Release Inventory
  TSCA: Toxic Substances Control Act
  TWA: time-weighted average
  U.K.: United Kingdom
  U.S.: United States of America
  USGS: United States Geological Survey
  UVC: ultraviolet C
  VC: vehicle control
  VEGF: vascular endothelial growth factor
  XPA: xeroderma pigmentosum complementation group A
  XPE: xeroderma pigmentosum complementation group E