# References

Agency for Toxic Substances Disease Registry (ATSDR). 1992. Toxicological profile for antimony and compounds. Atlanta, GA.
Agency for Toxic Substances Disease Registry (ATSDR). 2017. Draft toxicological profile for antimony and compounds. Atlanta, GA.
Al Jaser MH, Radwan MA, Zaghloul IY. 2006. Pharmacokinetics and tissue distribution of antimony(V) after multiple intramuscular administrations in the hamster. Saudi Pharm J. 14(1):52–58.
Amereih S, Meisel T, Scholger R, Wegscheider W. 2005. Antimony speciation in soil samples along two Austrian motorways by HPLC-ID-ICP-MS. Journal of environmental monitoring. JEM. 7(12):1200–1206. 16307072
American Conference of Governmental Industrial Hygienists (ACGIH). 2017. TLVs and BEIs based on the documentation of the threshold limit values for chemical substances and physical agents & biological indices. Cincinnati, OH: Association Advancing Occupational and Environmental Health.
Andrewes P, Kitchin KT, Wallace K. 2004. Plasmid DNA damage caused by stibine and trimethylstibine. Toxicol Appl Pharmacol. 194(1):41–48. 10.1016/j.taap.2003.08.012 14728978
Asakura K, Satoh H, Chiba M, Okamoto M, Serizawa K, Nakano M, Omae K. 2009. Genotoxicity studies of heavy metals: Lead, bismuth, indium, silver and antimony. J Occup Health. 51(6):498–512. 10.1539/joh.L9080 19851040
Bailly R, Lauwerys R, Buchet JP, Mahieu P, Konings J. 1991. Experimental and human studies on antimony metabolism: Their relevance for the biological monitoring of workers exposed to inorganic antimony. Br J Ind Med. 48(2):93–97. 10.1136/oem.48.2.93 1998614
Barrera C, López S, Aguilar L, Mercado L, Bravo M, Quiroz W. 2016. Pentavalent antimony uptake pathway through erythrocyte membranes: Molecular and atomic fluorescence approaches. Anal Bioanal Chem. 408(11):2937–2944. 10.1007/s00216-015-9188-y 26586161
Belova A, Greco SL, Riederer AM, Olsho LE, Corrales MA. 2013. A method to screen U.S. environmental biomonitoring data for race/ethnicity and income-related disparity. Environ Health. 12:114. 10.1186/1476-069X-12-114 24354733
Belyaeva AP. 1967. The effect produced by antimony on the generative function. Labor Hyg Occup Dis. 11:32–37.
Belzile N, Chen YW, Filella M. 2011. Human exposure to antimony: I. Sources and intake. Crit Rev Environ Sci Technol. 41(14):1309–1373. 10.1080/10643381003608227
Bento DB, de Souza B, Steckert AV, Dias RO, Leffa DD, Moreno SE, Petronilho F, de Andrade VM, Dal-Pizzol F, Romão PR. 2013. Oxidative stress in mice treated with antileishmanial meglumine antimoniate. Res Vet Sci. 95(3):1134–1141. 10.1016/j.rvsc.2013.08.004 24012348
Beyersmann D, Hartwig A. 2008. Carcinogenic metal compounds: Recent insight into molecular and cellular mechanisms. Arch Toxicol. 82(8):493–512. 10.1007/s00204-008-0313-y 18496671
Binks K, Doll R, Gillies M, Holroyd C, Jones SR, McGeoghegan D, Scott L, Wakeford R, Walker P. 2005. Mortality experience of male workers at a UK tin smelter. Occup Med (Lond). 55(3):215–226. 10.1093/occmed/kqi026 15757978
Blond DM, Whittam R. 1965. Effects of sodium and potassium ions on oxidative phosphorylation in relation to respiratory control by a cell-membrane adenosine triphosphatase. Biochem J. 97(2):523–531. 10.1042/bj0970523 16749159
Borborema SE, Osso JA Jr, Andrade HF Jr, Nascimento ND. 2013. Biodistribution of meglumine antimoniate in healthy and Leishmania (Leishmania) infantum chagasi-infected BALB/c mice. Mem Inst Oswaldo Cruz. 108(5):623–630. 10.1590/0074-0276108052013014 23903979
Brieger H, Semisch CW, Stasney J, Piatnek DA. 1954. Industrial antimony poisoning. Ind Med Surg. 23:521–523. 13211006
Burroughs GE, Horan J. 1981. Health hazard evaluation report. Becton-Dickinson Company. Columbus, Nebraska: National Institutes for Occupational Health and Safety;, HE 80-023-804.
Cantanhêde LF, Almeida LP, Soares REP, Branco PVGC, Pereira SRF. 2015. Soy isoflavones have antimutagenic activity on DNA damage induced by the antileishmanial Glucantime (meglumine antimoniate). Drug Chem Toxicol. 38(3):312–317. 10.3109/01480545.2014.963599 25268948
Cassady ME, Etchison B. 1976. Walk-through survey of Chemetron Corporation Inorganic Chemicals Division. Cincinnati, OH: Industrial Hygiene Section, Division of Surveillance, Hazard Evaluations, and Field Studies, National Institute for Occupational Safety and Health.
Cavallo D, Iavicoli I, Setini A, Marinaccio A, Perniconi B, Carelli G, Iavicoli S. 2002. Genotoxic risk and oxidative DNA damage in workers exposed to antimony trioxide. Environ Mol Mutagen. 40(3):184–189. 10.1002/em.10102 12355552
Centers for Diesase Control Prevention (CDC).2017. National Occupational Exposure Survey (NOES). Centers for Disease Control and Prevention.https://www.cdc.gov/noes/default.html. [Accessed on 11/20/17]
Centers for Disease Control Prevention (CDC). 1978. Criteria for a recommended standard. Occupational exposure to antimony. Washington, D.C.: U.S. Department of Health, Education, and Welfare, Center for Disease Control.
Centers for Disease Control Prevention (CDC).2016a. Health hazard evaluatiuons (HHEs) search. Centers for Disease Control and Prevention.https://www2a.cdc.gov/hhe/search.asp. [Accessed on 11/20/17]
Centers for Disease Control Prevention (CDC).2016b. Leishmaniasis. Resources for health professionals. Centers for Disease Control and Prevention.https://www.cdc.gov/parasites/leishmaniasis/health_professionals/index.html. [Accessed on 6/9/17]
Centers for Disease Control Prevention (CDC).2017a. Fourth national report on human exposure to environmental chemicals, updated tables, January 2017, Volume 1. Atlanta, GA: Centers for Disease Control and Prevention.https://www.cdc.gov/exposurereport/.
Centers for Disease Control Prevention (CDC).2017b. Fourth national report on human exposure to environmental chemicals, updated tables, January 2017, Volume 2. Atlanta, GA: Centers for Disease Control and Prevention.https://www.cdc.gov/exposurereport/pdf/FourthReport_UpdatedTables_Volume2_Jan2017.pdf.
Chandra S, Hoenerhoff MJ, Peterson R. 2013. Chapter 17, Endocrine glands. In: Sahota PS, Popp JA, Hardisty JF, Gopinath C, editors. Toxiologic Pathology: Nonclinical Safety Assessment. Boca Raton, FL: CRC Press; p. 691.
ChemIDplus.2017. ChemIDplus Advanced. National Library of Medicine.http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp. [Accessed on 5/22/17]
ChemSpider.2017. Potassium antimonate(V). Royal Society of Chemistry.http://www.chemspider.com/Chemical-Structure.11311229.html. [Accessed on 11/20/17]
Chiu WA, Guyton KZ, Martin MT, Reif DM, Rusyn I. 2017. Use of high-throughput in vitro toxicity screening data in cancer hazard evaluations by IARC Monograph Working Groups. ALTEX. 35(1):14. 28738424
Coelho DR, De-Carvalho RR, Rocha RCC, Saint’Pierre TD, Paumgartten FJR. 2014. Effects of in utero and lactational exposure to Sb-V on rat neurobehavioral development and fertility. Reprod Toxicol. 50:98–107. 10.1016/j.reprotox.2014.10.016 25461908
Colak EH, Yomralioglu T, Nisanci R, Yildirim V, Duran C. 2015. Geostatistical analysis of the relationship between heavy metals in drinking water and cancer incidence in residential areas in the Black Sea region of Turkey. J Environ Health. 77(6):86–93. 25619041
Craig AB, Jr., Vandervort R, Burton DJ, Coleman RT. 1981. Environmental and occupational protection in the secondary lead industry. DHHS (NIOSH) Pub1 ISS 81-114
Cullen A, Kiberd B, Matthews T, Mayne P, Delves HT, O’Regan M. 1998. Antimony in blood and urine of infants. J Clin Pathol. 51(3):238–240. 10.1136/jcp.51.3.238 9659268
Daskalos A, Logotheti S, Markopoulou S, Xinarianos G, Gosney JR, Kastania AN, Zoumpourlis V, Field JK, Liloglou T. 2011. Global DNA hypomethylation-induced DeltaNp73 transcriptional activation in non-small cell lung cancer. Cancer Lett. 300(1):79–86. 10.1016/j.canlet.2010.09.009 20926182
Daskalos A, Nikolaidis G, Xinarianos G, Savvari P, Cassidy A, Zakopoulou R, Kotsinas A, Gorgoulis V, Field JK, Liloglou T. 2009. Hypomethylation of retrotransposable elements correlates with genomic instability in non-small cell lung cancer. Int J Cancer. 124(1):81–87. 10.1002/ijc.23849 18823011
De Gregori I, Quiroz W, Pinochet H, Pannier F, Potin-Gautier M. 2007. Speciation analysis of antimony in marine biota by HPLC-(UV)-HG-AFS: Extraction procedures and stability of antimony species. Talanta. 73(3):458–465. 10.1016/j.talanta.2007.04.015 19073056
De Oliveira FB, Schettini DA, Ferreira CS, Rates B, Rocha OGF, Frézard F, Demicheli C. 2006. Kinetics of antimony(V) reduction by L-cysteine. Pharmacological implications and application to the determination of antimony in pentavalent antimonial drugs. J Braz Chem Soc. 17(8):1642–1650. 10.1590/S0103-50532006000800023
de Ricciardi LV, Vicuña-Fernández N, de Peña YP, López S, Scorza JV, Scorza-Dager JV, Villegas E, Pérez B. 2008. Pharmacokinetic disposition of antimony species in dogs after a dose of meglumine antimonate (Glucantime®). Bol Malariol Salud Ambient. 48(1):27–33.
Donaldson H. 1976. Industrial Hygiene Survey of Texas Smelting and Refining Division of National Lead Industries, Laredo, Texas. Cincinnati, OH: U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control, National Institute for Occupational Safety and Health.
Donaldson H, Gentry S. 1975. Air Sampling Industrial Hygiene Survey: The Harshaw Chemical Company, Gloucester City, New Jersey. Cincinnati, OH: Department of Health, Education and Welfare, Division of Surveillance, Hazard Evaluations, and Field Studies, National Institute for Occupational Safety and Health.
Dopp E, Hartmann LM, Florea AM, von Recklinghausen U, Rabieh S, Shokouhi B, Hirner AV, Rettenmeier AW. 2006. Trimethylantimony dichloride causes genotoxic effects in Chinese hamster ovary cells after forced uptake. Toxicol In Vitro. 20(6):1060–1065. 10.1016/j.tiv.2006.01.018 16527445
Dunn JT. 1928. A curious case of antimony poisoning. Analyst (Lond). 53:532–533.
Dupont D, Arnout S, Jones PT, Binnemans K. 2016. Antimony recovery from end-of-life products and industrial process residues: A critical review. J Sustain Metall. 2:79–103. 10.1007/s40831-016-0043-y
Edel J, Marafante E, Sabbioni E, Manzo L.1983. Metabolic behaviour of inorganic forms of antimony in the rat. In: International Conference on Heavy Metals in the Environment, Heidelberg, West Germany, September 1983. Edinburgh, UK: CEP Consultants. p. 574-577.
El Nahas S, Temtamy SA, de Hondt HA. 1982. Cytogenetic effect of two antimonial antibilharzial drugs: Tartar emetic and bilharcid. Environ Mutagen. 4(1):83–91. 10.1002/em.2860040111 6896028
El Shanawany S, Foda N, Hashad DI, Salama N, Sobh Z. 2017. The potential DNA toxic changes among workers exposed to antimony trioxide. Environ Sci Pollut Res Int. 24(13):12455–12461. 10.1007/s11356-017-8805-z 28361399
Ellegaard L, Cunningham A, Edwards S, Grand N, Nevalainen T, Prescott M, Schuurman T, Steering Group of the Rethink Project. 2010. Welfare of the minipig with special reference to use in regulatory toxicology studies. J Pharmacol Toxicol Methods. 62(3):167–183. 10.1016/j.vascn.2010.05.006 20621655
Elliott BM, Mackay JM, Clay P, Ashby J. 1998. An assessment of the genetic toxicology of antimony trioxide. Mutat Res. 415(1-2):109–117. 10.1016/S1383-5718(98)00065-5 9711267
Elshafie AI, Åhlin E, Mathsson L, ElGhazali G, Rönnelid J. 2007. Circulating immune complexes (IC) and IC-induced levels of GM-CSF are increased in sudanese patients with acute visceral Leishmania donovani infection undergoing sodium stibogluconate treatment: implications for disease pathogenesis. Journal of immunology (Baltimore, Md: 1950). 178(8):5383-5389.
EpiSuite.2017. Antimony pentoxide. U.S. Environmental Protection Agency.https://comptox.epa.gov/dashboard/dsstoxdb/results?utf8=%E2%9C%93&search=1314-60-9. [Accessed on 5/30/17]
European Chemicals Agency (ECHA).2017. Diantimony pentoxide. European Chemicals Agency.https://echa.europa.eu/registration-dossier/-/registered-dossier/16264/7/2/2. [Accessed on 10/3/17]
European Union (EU). 2008. European Union risk assessment report. Diantimony Trioxide. Luxembourg: European Communities.
Fabian T, Borgerson JL, Kerber SI, Gandhi PD, Baxter CS, Ross CS, Lockey JE, Dalton JM.2010. Firefighter exposure to smoke particulates. Underwriter Laboratories, Inc. Project Number: 08CA31673, File Number: IN 15941.https://ulfirefightersafety.org/assets/EMW-2007-FP-02093-cebf37283b5f736fe7dd535dcf26382e5b5b5d5e911d8b28af6fed60ad0b6e6a.pdf.
Fan K, Borden E, Yi T. 2009. Interferon-gamma is induced in human peripheral blood immune cells in vitro by sodium stibogluconate/interleukin-2 and mediates its antitumor activity in vivo. J Interferon Cytokine Res. 29(8):451–460. 10.1089/jir.2008.0061 19514839
Felicetti SA, Thomas RG, McClellann RO. 1974 a. Metabolism of two valence states of inhaled antimony in hamsters. Am Ind Hyg Assoc J. 35(5):292–300. 10.1080/0002889748507037 4208632
Felicetti SW, Thomas RG, McClellan RO. 1974 b. Retention of inhaled antimony-124 in the beagle dog as a function of temperature of aerosol formation. Health Phys. 26(6):525–531. 10.1097/00004032-197406000-00006 4209292
Fernandes FR, Ferreira WA, Campos MA, Ramos GS, Kato KC, Almeida GG, Corrêa JD Jr, Melo MN, Demicheli C, Frézard F. 2013. Amphiphilic antimony(V) complexes for oral treatment of visceral leishmaniasis. Antimicrob Agents Chemother. 57(9):4229–4236. 10.1128/AAC.00639-13 23796930
Filella M, Belzile N, Chen YW. 2002 a. Antimony in the environment: A review focused on natural waters I. Occurence. Earth Sci Rev. 57(1-2):125–176. 10.1016/S0012-8252(01)00070-8
Filella M, Belzile N, Chen YW. 2002 b. Antimony in the environment: A review focused on natural waters II. Relevant solution chemistry. Earth Sci Rev. 59(1-4):265–285. 10.1016/S0012-8252(02)00089-2
Filella M, Belzile N, Chen YW. 2013 a. Human exposure to antimony. III. Contents in some human excreted biofluids (urine, milk, saliva). Crit Rev Environ Sci Technol. 43:162–214. 10.1080/10643389.2011.604257
Filella M, Belzile N, Chen YW. 2013 b. Human exposure to antimony. IV. Contents in human blood. Crit Rev Environ Sci Technol. 43(19):2071–2105. 10.1080/10643389.2013.790741
Filella M, Belzile N, Lett MC. 2007. Antimony in the environment: A review focused on natural waters. III. Microbiota relevant interactions. Earth Sci Rev. 80:195–217. 10.1016/j.earscirev.2006.09.003
Friedrich K, Vieira FA, Porrozzi R, Marchevsky RS, Miekeley N, Grimaldi G Jr, Paumgartten FJ. 2012. Disposition of antimony in rhesus monkeys infected with Leishmania braziliensis and treated with meglumine antimoniate. J Toxicol Environ Health A. 75(2):63–75. 10.1080/15287394.2012.624826 22129235
Garg SP, Singh IS, Sharma RC. 2003. Long term lung retention studies of ^125^Sb aerosols in humans. Health Phys. 84(4):457–468. 10.1097/00004032-200304000-00005 12705444
Gebel T. 1998. Suppression of arsenic-induced chromosome mutagenicity by antimony. Mutat Res. 412(3):213–218. 10.1016/S1383-5718(97)00181-2 9600688
Gebel T, Birkenkamp P, Luthin S, Dunkelberg H. 1998. Arsenic(III), but not antimony(III), induces DNA-protein crosslinks. Anticancer Res. 18 6a:4253–4257. 9891475
Gebel T, Christensen S, Dunkelberg H. 1997. Comparative and environmental genotoxicity of antimony and arsenic. Anticancer Res. 17 4a:2603–2607. 9252688
Gerhardsson L, Brune D, Nordberg GF, Wester PO. 1982. Antimony in lung, liver and kidney tissue from deceased smelter workers. Scand J Work Environ Health. 8(3):201–208. 10.5271/sjweh.2475 7156939
Gerhardsson L, Nordberg GF. 1993. Lung cancer in smelter workers – interactions of metals as indicated by tissue levels. Scand J Work Environ Health. 19 Suppl 1:90–94. 8159982
Ghosh M, Roy K, Roy S. 2013. Immunomodulatory effects of antileishmanial drugs. J Antimicrob Chemother. 68(12):2834–2838. 10.1093/jac/dkt262 23833177
Gietl JK, Lawrence R, Thorpe AJ, Harrison RM. 2010. Identification of brake wear particles and derivation of a quantitative tracer for brake dust at a major road. Atmos Environ. 44:141–146. 10.1016/j.atmosenv.2009.10.016
Goi G, Bairati C, Massaccesi L, Sarnico M, Pagani A, Lombardo A, Apostoli P. 2003. Low levels of occupational exposure to arsenic and antimony: Effects on lysosomal glycohydrolase levels in plasma of exposed workers and in lymphocyte cultures. Am J Ind Med. 44(4):405–412. 10.1002/ajim.10283 14502769
Gonzales FA, Jones RR, Deardorff J, Windham GC, Hiatt RA, Kushi LH. 2016. Neighborhood deprivation, race/ethnicity, and urinary metal concentrations among young girls in California. Environ Int. 91:29–39. 10.1016/j.envint.2016.02.004 26908165
Gosney JR. 1985. Adrenal corticomedullary hyperplasia in hypobaric hypoxia. J Pathol. 146(1):59–64. 10.1002/path.1711460107 4009322
Gross P, Brown JH, Westrick ML, Srsic RP, Butler NL, Hatch TF. 1955. Toxicologic study of calcium halophosphate phosphors and antimony trioxide. I. Acute and chronic toxicity and some pharmacologic aspects. AMA Arch Ind Health. 11(6):473–478. 14375403
Grosskopf C, Schwerdtle T, Mullenders LH, Hartwig A. 2010. Antimony impairs nucleotide excision repair: XPA and XPE as potential molecular targets. Chem Res Toxicol. 23(7):1175–1183. 10.1021/tx100106x 20509621
Groth DH, Stettler LE, Burg JR, Busey WM, Grant GC, Wong L. 1986. Carcinogenic effects of antimony trioxide and antimony ore concentrate in rats. J Toxicol Environ Health. 18(4):607–626. 10.1080/15287398609530898 3735460
Grund SB, Hanusch K, Breunig HJ, Wolf HU. 2011. Ullman’s Encyclopedia of Industrial Chemistry. Weinheim: Wiley-VCH Verlag GmbH & Co.; Antimony and antimony compounds; p. 12–41.
Guo J, Su L, Zhao X, Xu Z, Chen G. 2016. Relationships between urinary antimony levels and both mortalities and prevalence of cancers and heart diseases in general US population, NHANES 1999-2010. Sci Total Environ. 571:452–460. 10.1016/j.scitotenv.2016.07.011 27396316
Gurnani N, Sharma A, Talukder G. 1992a. Comparison of the clastogenic effects of antimony trioxide on mice in vivo following acute and chronic exposure. Biometals: an international journal on the role of metal ions in biology, biochemistry, and medicine. 5(1):47-50.
Gurnani N, Sharma A, Talukder G. 1992 b. Cytotoxic effects of antimony trichloride on mice in vivo. Cytobios. 70(281):131–136. 1451533
Hansen C, Hansen EW, Hansen HR, Gammelgaard B, Stürup S. 2011. Reduction of Sb(V) in a human macrophage cell line measured by HPLC-ICP-MS. Biol Trace Elem Res. 144(1-3):234–243. 10.1007/s12011-011-9079-9 21618006
Hashemzaei M, Pourahmad J, Safaeinejad F, Tabrizian K, Akbari F, Bagheri G, Hosseini MJ, Shahraki J. 2015. Antimony induces oxidative stress and cell death in normal hepatocytes. Toxicol Environ Chem. 97(2):256–265. 10.1080/02772248.2015.1032616
Hazardous Substances Data Bank.2013. Hazardous Substances Data Bank: Antimony trioxide. National Library of Medicine.http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB. [Accessed on 5/19/17]
Health Canada. 2010. Screening Assessment for the Challenge: Antimony Trioxide. Health Canada.
Herath I, Vithanage M, Bundschuh J. 2017. Antimony as a global dilemma: Geochemistry, mobility, fate and transport. Environmental pollution (Barking, Essex: 1987). 223:545-559. 10.1016/j.envpol.2017.01.057
Hirano K, Hagiwara T, Ohta Y, Matsumoto H, Kada T. 1982. rec-Assay with spores of Bacillus subtilis with and without metabolic activation. Mutat Res. 97(5):339–347. 10.1016/0165-1161(82)90001-2 6815526
Hiza RJ, Aguilar GA, Donnelly SG, Cheng FS, Tepper RJ.2006. Lubricating greases containing antimony dithiocarbamates. Patent US 2006/0183648 A1
Howlader N, Noone AM, Krapcho M, Miller D, Bishop K, Kosary CL, Yu M, Ruhl J, Tatalovich Z, Mariotto A, et al. 2017. SEER Cancer Statistics Review, 1975-2014. Bethesda, MD: National Cancer Institute;. https://seer.cancer.gov/csr/1975_2014/.
Huang H, Shu SC, Shih JH, Kuo CJ, Chiu ID. 1998. Antimony trichloride induces DNA damage and apoptosis in mammalian cells. Toxicology. 129(2-3):113–123. 10.1016/S0300-483X(98)00073-0 9772090
Huang W, Qi CB, Lv SW, Xie M, Feng YQ, Huang WH, Yuan BF. 2016. Determination of DNA and RNA methylation in circulating tumor cells by mass spectrometry. Anal Chem. 88(2):1378–1384. 10.1021/acs.analchem.5b03962 26707930
Iavicoli I, Caroli S, Alimonti A, Petrucci F, Carelli G. 2002. Biomonitoring of a worker population exposed to low antimony trioxide levels. J Trace Elem Med Biol. 16(1):33–39. 10.1016/S0946-672X(02)80006-2 11878750
Ingenuity Systems.2018. Ingenuity upstream regulator analysis in IPA. Ingenuity Systems.http://pages.ingenuity.com/rs/ingenuity/images/0812%20upstream_regulator_analysis_whitepaper.pdf.
International Agency for Research on Cancer (IARC). 1989. Some Organic Solvents, Resin Monomers and Related Compounds, Pigments and Occupational Exposures in Paint Manufacture and Painting. Lyon, France: International Agency for Research on Cancer; Antimony trioxide and antimony trisulfide; p. 291–305.
International Agency for Research on Cancer (IARC). 2006. Cobalt in Hard Metals and Cobalt Sulfate, Gallium Arsenide, Indium Phosphide and Vanadium Pentoxide. Lyon, France: International Agency for Research on Cancer; Metallic cobalt particles (with or without tungsten carbide); p. 39–155.
International Agency for Research on Cancer (IARC).2017a. List of classifications by cancer sites with sufficient or limited evidence in humans, Volumes 1 to 119. International Agency for Research on Cancer.https://monographs.iarc.fr/ENG/Classification/Table4.pdf. [Updated 4/13/17]
International Agency for Research on Cancer (IARC). 2017 b. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Lyon, France: International Agency for Research on Cancer; Some organophosphate insecticides and herbicides; p. 464.
International Commission on Radiological Protection (ICRP). 1981. Metabolic data for antimony. Ann ICRP. 6(2-3):46–49. 10.1016/0146-6453(81)90098-1
International Programme on Chemical Safety.2017. Antimony trioxide. International Programme on Chemical Safety.http://www.inchem.org/documents/icsc/icsc/eics0012.htm. [Accessed on 10/26/17]
Internationl Commission on Radiological Protection (ICRP). 2012. Draft report: Occupational intakes of radionucleotides, Part 3. International Commission on Radiological Protection. ICRP ref 4838-4528-4881
Jenkins RO, Craig PJ, Goessler W, Irgolic KJ. 1998. Antimony leaching from cot mattresses and sudden infant death syndrome (SIDS). Hum Exp Toxicol. 17(3):138–139. 10.1177/096032719801700302 9587780
Johns Hopkins University.2017. Species specific information: Rat. Johns Hopkins University.https://web.jhu.edu/animalcare/procedures/rat.html. [Accessed on 8/18/17]
Jones DP. 2008. Radical-free biology of oxidative stress. Am J Physiol Cell Physiol. 295(4):C849–C868. 10.1152/ajpcell.00283.2008 18684987
Jones RD. 1994. Survey of antimony workers: Mortality 1961-1992. Occup Environ Med. 51(11):772–776. 10.1136/oem.51.11.772 7849856
Jones SR, Atkin P, Holroyd C, Lutman E, Batlle JV, Wakeford R, Walker P. 2007. Lung cancer mortality at a UK tin smelter. Occup Med (Lond). 57(4):238–245. 10.1093/occmed/kql153 17437956
Jones W, Gamble J. 1984. Epidemiological-environmental study of lead acid battery workers. I. Environmental study of five lead acid battery plants. Environ Res. 35(1):1–10. 10.1016/0013-9351(84)90110-5 6489281
Kada T. 1976. Rec assay with cold incubation with and without metabolic reactivation in vitro [proceedings]. Mutat Res. 38(5):340. 10.1016/0165-1161(76)90166-7 823428
Kanematsu N, Hara M, Kada T. 1980. Rec assay and mutagenicity studies on metal compounds. Mutat Res. 77(2):109–116. 10.1016/0165-1218(80)90127-5 6769036
Kanisawa M, Schroeder HA. 1969. Life term studies on the effect of trace elements on spontaneous tumors in mice and rats. Cancer Res. 29(4):892–895. 5777793
Kavlock R, Chandler K, Houck K, Hunter S, Judson R, Kleinstreuer N, Knudsen T, Martin M, Padilla S, Reif D, et al. 2012. Update on EPA’s ToxCast program: Providing high throughput decision support tools for chemical risk management. Chem Res Toxicol. 25(7):1287–1302. 10.1021/tx3000939 22519603
Kavlock R, Dix D. 2010. Computational toxicology as implemented by the U.S. EPA: Providing high throughput decision support tools for screening and assessing chemical exposure, hazard and risk. J Toxicol Environ Health B Crit Rev. 13(2-4):197–217. 10.1080/10937404.2010.483935 20574897
Kawata K, Yokoo H, Shimazaki R, Okabe S. 2007. Classification of heavy-metal toxicity by human DNA microarray analysis. Environ Sci Technol. 41(10):3769–3774. 10.1021/es062717d 17547211
Kentner M, Leinemann M, Schaller KH, Weltle D, Lehnert G. 1995. External and internal antimony exposure in starter battery production. Int Arch Occup Environ Health. 67(2):119–123. 10.1007/BF00572235 7672855
Kim HA, Heo Y, Oh SY, Lee KJ, Lawrence DA. 1999. Altered serum cytokine and immunoglobulin levels in the workers exposed to antimony. Hum Exp Toxicol. 18(10):607–613. 10.1191/096032799678839400 10557011
Kim HS, Kim YJ, Seo YR. 2015. An overview of carcinogenic heavy metal: Molecular toxicity mechanism and prevention. J Cancer Prev. 20(4):232–240. 10.15430/JCP.2015.20.4.232 26734585
Kirkland D, Whitwell J, Deyo J, Serex T. 2007. Failure of antimony trioxide to induce micronuclei or chromosomal aberrations in rat bone-marrow after sub-chronic oral dosing. Mutat Res. 627(2):119–128. 10.1016/j.mrgentox.2006.10.012 17174592
Koch B, Maser E, Hartwig A. 2017. Low concentrations of antimony impair DNA damage signaling and the repair of radiation-induced DSB in HeLa S3 cells. Arch Toxicol. 10.1007/s00204-017-2004-z 28612261
Kocyigit A, Gur S, Gurel MS, Bulut V, Ulukanligil M. 2002. Antimonial therapy induces circulating proinflammatory cytokines in patients with cutaneous leishmaniasis. Infect Immun. 70(12):6589–6591. 10.1128/IAI.70.12.6589-6591.2002 12438329
Krachler M, Emons H. 2001. Urinary antimony speciation by HPLC-ICP-MS. J Anal At Spectrom. 16(1):20–25. 10.1039/B007903K
Krupka KM, Serne RJ.2002. Geochemical factors affecting the behavior of antimony, cobalt, europium, technetium, and uranium in vadose sediments. Oak Ridge, TN: Pacific Northwest Laboratory. PNNL-14126 10.2172/15004491
Kuroda K, Endo G, Okamoto A, Yoo YS, Horiguchi S. 1991. Genotoxicity of beryllium, gallium and antimony in short-term assays. Mutat Res. 264(4):163–170. 10.1016/0165-7992(91)90072-C 1723493
Lantzsch H, Gebel T. 1997. Genotoxicity of selected metal compounds in the SOS chromotest. Mutat Res. 389(2-3):191–197. 10.1016/S1383-5718(96)00146-5 9093383
Lauwers LF, Roelants A, Rosseel PM, Heyndrickx B, Baute L. 1990. Oral antimony intoxications in man. Crit Care Med. 18(3):324–326. 10.1097/00003246-199003000-00017 2302961
Lecureur V, Lagadic-Gossmann D, Fardel O. 2002. Potassium antimonyl tartrate induces reactive oxygen species-related apoptosis in human myeloid leukemic HL60 cells. Int J Oncol. 20(5):1071–1076. 10.3892/ijo.20.5.1071 11956606
Leffler P, Gerhardsson L, Brune D, Nordberg GF. 1984. Lung retention of antimony and arsenic in hamsters after the intratracheal instillation of industrial dust. Scand J Work Environ Health. 10(4):245–251. 10.5271/sjweh.2330 6541805
Li J, Wei Y, Zhao L, Zhang J, Shangguan Y, Li F, Hou H. 2014. Bioaccessibility of antimony and arsenic in highly polluted soils of the mine area and health risk assessment associated with oral ingestion exposure. Ecotoxicol Environ Saf. 110:308–315. 10.1016/j.ecoenv.2014.09.009 25437466
Lian CG, Xu S, Guo W, Yan J, Frank MY, Liu R, Liu C, Chen Y, Murphy GF, Chen T. 2015. Decrease of 5-hydroxymethylcytosine in rat liver with subchronic exposure to genotoxic carcinogens riddelliine and aristolochic acid. Mol Carcinog. 54(11):1503–1507. 10.1002/mc.22201 25154389
López S, Aguilar L, Mercado L, Bravo M, Quiroz W. 2015. Sb(V) reactivity with human blood components: Redox effects. PLoS One. 10(1):12. 10.1371/journal.pone.0114796 25615452
Lösler S, Schlief S, Kneifel C, Thiel E, Schrezenmeier H, Rojewski MT. 2009. Antimony-trioxide- and arsenic-trioxide-induced apoptosis in myelogenic and lymphatic cell lines, recruitment of caspases, and loss of mitochondrial membrane potential are enhanced by modulators of the cellular glutathione redox system. Ann Hematol. 88(11):1047–1058. 10.1007/s00277-009-0736-4 19301004
Lüdersdorf R, Fuchs A, Mayer P, Skulsuksai G, Schäcke G. 1987. Biological assessment of exposure to antimony and lead in the glass-producing industry. Int Arch Occup Environ Health. 59(5):469–474. 10.1007/BF00377841 3653992
Majestic BJ, Turner JA, Marcotte AR. 2012. Respirable antimony and other trace-elements inside and outside an elementary school in Flagstaff, AZ, USA. Sci Total Environ. 435-436:253–261. 10.1016/j.scitotenv.2012.07.020 22858533
Mak. 2007. Antimony and its inorganic compounds (inhalable fraction). In: The MAK-Collection Part I: MAK Value Documentations. Weinheim, Germany: WILEY-VCH Verlag GmbH & Co. KGaA.
Mann KK, Davison K, Colombo M, Colosimo AL, Diaz Z, Padovani AM, Guo Q, Scrivens PJ, Gao W, Mader S, et al. 2006. Antimony trioxide-induced apoptosis is dependent on SEK1/JNK signaling. Toxicol Lett. 160(2):158–170. 10.1016/j.toxlet.2005.06.017 16112521
Mapei Group.2017. Technical Notebook: Hexavalent Chromium Reducing Agents for Portland Cements and Cement-Based Materials. Milan, Italy: C-ADD Division, Maipei Group.http://cadd.mapei.com/wp-content/uploads/2016/02/mapei-dam-cement-reducing-agents-technical-notebook.pdf.
Miekeley N, Mortari SR, Schubach AO. 2002. Monitoring of total antimony and its species by ICP-MS and on-line ion chromatography in biological samples from patients treated for leishmaniasis. Anal Bioanal Chem. 372(3):495–502. 10.1007/s00216-001-1213-7 11939540
Migliore L, Cocchi L, Nesti C, Sabbioni E. 1999. Micronuclei assay and FISH analysis in human lymphocytes treated with six metal salts. Environ Mol Mutagen. 34(4):279–284. 10.1002/(SICI)1098-2280(1999)34:4<279::AID-EM8>3.0.CO;2-7 10618176
Miranda ES, Miekeley N, De-Carvalho RR, Paumgartten FJ. 2006. Developmental toxicity of meglumine antimoniate and transplacental transfer of antimony in the rat. Reprod Toxicol. 21(3):292–300. 10.1016/j.reprotox.2005.09.010 16271447
Molokhia MM, Smith H. 1967. Trace elements in the lung. Arch Environ Health. 15(6):745–750. 10.1080/00039896.1967.10664992 6061299
Moreira VR, de Jesus LCL, Soares RP, Silva LDM, Pinto BAS, Melo MN, Paes AMA, Pereira SRF. 2017. Meglumine antimoniate (glucantime) causes oxidative stress-derived DNA damage in BALB/c mice infected by Leishmania (Leishmania) infantum. Antimicrob Agents Chemother. 61(6). 10.1128/AAC.02360-16 28320726
Morrow PE. 1988. Possible mechanisms to explain dust overloading of the lungs. Fundamental and applied toxicology: official journal of the Society of Toxicology. 10(3):369-384.
Morrow PE. 1992. Dust overloading of the lungs: Update and appraisal. Toxicol Appl Pharmacol. 113(1):1–12. 10.1016/0041-008X(92)90002-A 1553742
Müller K, Daus B, Mattusch J, Stärk HJ, Wennrich R. 2009. Simultaneous determination of inorganic and organic antimony species by using anion exchange phases for HPLC-ICP-MS and their application to plant extracts of Pteris vittata. Talanta. 78(3):820–826. 10.1016/j.talanta.2008.12.059 19269435
Murray HW, Delph-Etienne S. 2000. Roles of endogenous gamma interferon and macrophage microbicidal mechanisms in host response to chemotherapy in experimental visceral leishmaniasis. Infect Immun. 68(1):288–293. 10.1128/IAI.68.1.288-293.2000 10603400
National Center for Biotechnology Information (NCBI).2017. GEO Datasets. Bethesda, MD: National Center for Biotechnology Information, U.S. National Library of Medicine.https://www.ncbi.nlm.nih.gov/gds/. [Accessed: November 20, 2017]
National Research Council (NRC). 1999. Health Effects of Exposure to Radon: BEIR VI. Washington, D.C.: National Academy Press.
National Toxicology Progam (NTP).1992. NTP technical report report on the toxicity studies of antimony potassium tartrate in F344/N rats and B6C3F1 mice (drinking water and intraperitoneal injection studies). Research Triangle Park, NC: National Toxicology Program. Toxicity Report 11
National Toxicology Program (NTP).1985. NTP toxicology and carcinogenesis studies of dimethyl hydrogen phosphite (CAS No. 868-85-9) in F344/N rats and B6C3F1 mice (gavage studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 287.https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr287.pdf.
National Toxicology Program (NTP).1990. NTP toxicology and carcinogenesis studies of tetranitromethane (CAS No. 509-14-8) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 386.https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr386.pdf.
National Toxicology Program (NTP).1996a. NTP toxicology and carcinogenesis studies of nickel oxide (CAS No. 1313-99-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 451.https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr451.pdf.
National Toxicology Program (NTP).1996b. NTP toxicology and carcinogenesis studies of nickel subsulfide (CAS No. 12035-72-2) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 453.https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr453.pdf.
National Toxicology Program (NTP).1998. NTP toxicology and carcinogenesis studies of cobalt sulfate heptahydrate (CAS No. 10026-24-1) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 471.https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr471.pdf.
National Toxicology Program (NTP).2001. NTP toxicology and carcinogenesis studies of indium phosphide (CAS No. 22398-80-7) in F344/N rats and B6C3F1 mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program, National Institutes of Health. Technical Report 499.https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr499.pdf.
National Toxicology Program (NTP).2006. NTP toxicology and carcinogenesis studies of 3,3’,4,4’,5-pentachlorobiphenyl (PCB 126) (CAS No. 57465-28-8) in female Harlan Sprague-Dawley rats (gavage studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 520.https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr520.pdf.
National Toxicology Program (NTP).2015. Handbook for preparing the report on carcinogens monographs. Research Triangle Park, NC: National Toxicology Program.https://ntp.niehs.nih.gov/ntp/roc/handbook/roc_handbook_508.pdf.
National Toxicology Program (NTP).2017a. NTP toxicology and carcinogenesis studies of antimony trioxide (CAS No. 1309-64-4) in Wistar Han [Crl:WI (Han)] rats and B6C3F1/N mice (inhalation studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 590.https://ntp.niehs.nih.gov/ntp/htdocs/lt_rpts/tr590_508.pdf.
National Toxicology Program (NTP).2017b. Report on carcinogens protocol: Methods for preparing the draft report on carcinogens monograph on antimony trioxide and other antimony compounds. Research Triangle Park, NC: National Toxicology Program.https://ntp.niehs.nih.gov/ntp/roc/protocols/antimonytrioxide_508.pdf.
National Toxicology Program (NTP).2017c. Tox21 Toolbox. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health.https://ntp.niehs.nih.gov/results/tox21/tbox/. [Accessed: October 10, 2017]
Newton PE, Bolte HF, Daly IW, Pillsbury BD, Terrill JB, Drew RT, Ben-Dyke R, Sheldon AW, Rubin LF. 1994. Subchronic and chronic inhalation toxicity of antimony trioxide in the rat. Fundamental and applied toxicology: official journal of the Society of Toxicology. 22(4):561-576.
Nielson KB, Atkin CL, Winge DR. 1985. Distinct metal-binding configurations in metallothionein. J Biol Chem. 260(9):5342–5350. 10.1016/S0021-9258(18)89027-5 3988757
Nishioka H. 1975. Mutagenic activities of metal compounds in bacteria. Mutat Res. 31(3):185–189. 10.1016/0165-1161(75)90088-6 805366
Occupational Safety and Health Administration (OSHA).2017. Chemical exposure health data. United States Department of Labor.https://www.osha.gov/opengov/healthsamples.html. [Accessed on 7/28/17]
Olmez I, Gulovali MC, Gordon GE, Henkin RI. 1998. Trace elements in human parotid saliva. Biol Trace Elem Res. 17:259–270. 10.1007/BF02795462 2484364
Organisation for Economic Co-operation Development (OECD). 2016. Test No. 474: Mammalian erythrocyte micronucleus test. Paris. Paris: OECD Publishing.https://www.oecd-ilibrary.org/environment/test-no-474-mammalian-erythrocyte-micronucleus-test_9789264264762-en
Organisation for Economic Co-operation Development (OECD). 2017. Test No. 413: Subchronic inhalation toxicity: 90-Day study. Paris. Paris: OECD Publishing.https://www.oecd-ilibrary.org/environment/test-no-413-subchronic-inhalation-toxicity-90-day-study_9789264070806-en
Otto GF, Maren TH, Brown HW. 1947. Blood levels and excretion rates of antimony in persons receiving trivalent and pentavalent antimonials. Am J Hyg. 46:193–211. 20262045
Ozaki K, Haseman JK, Hailey JR, Maronpot RR, Nyska A. 2002. Association of adrenal pheochromocytoma and lung pathology in inhalation studies with particulate compounds in the male F344 rat – the National Toxicology Program experience. Toxicol Pathol. 30(2):263–270. 10.1080/019262302753559605 11950170
Pang Y, Peng RD, Jones MR, Francesconi KA, Goessler W, Howard BV, Umans JG, Best LG, Guallar E, Post WS, et al. 2016. Metal mixtures in urban and rural populations in the US: The Multi-Ethnic Study of Atherosclerosis and the Strong Heart Study. Environ Res. 147:356–364. 10.1016/j.envres.2016.02.032 26945432
Paßlack N, Mainzer B, Lahrssen-Wiederholt M, Schafft H, Palavinskas R, Breithaupt A, Zentek J. 2014. Liver and kidney concentrations of strontium, barium, cadmium, copper, zinc, manganese, chromium, antimony, selenium and lead in cats. BMC Vet Res. 10:9. 10.1186/1746-6148-10-163 24406022
Paßlack N, Mainzer B, Lahrssen-Wiederholt M, Schafft H, Palavinskas R, Breithaupt A, Zentek J. 2015. Concentrations of strontium, barium, cadmium, copper, zinc, manganese, chromium, antimony, selenium, and lead in the liver and kidneys of dogs according to age, gender, and the occurrence of chronic kidney disease. J Vet Sci. 16(1):57–66. 10.4142/jvs.2015.16.1.57 25234328
Pathak MK, Yi T. 2001. Sodium stibogluconate is a potent inhibitor of protein tyrosine phosphatases and augments cytokine responses in hemopoietic cell lines. Journal of immunology (Baltimore, Md: 1950). 167(6):3391-3397. 10.4049/jimmunol.167.6.3391
Paton GR, Allison AC. 1972. Chromosome damage in human cell cultures induced by metal salts. Mutat Res. 16(3):332–336. 10.1016/0027-5107(72)90166-2 5078138
Patterson TJ, Ngo M, Aronov PA, Reznikova TV, Green PG, Rice RH. 2003. Biological activity of inorganic arsenic and antimony reflects oxidation state in cultured human keratinocytes. Chem Res Toxicol. 16(12):1624–1631. 10.1021/tx034146y 14680377
Patterson TJ, Rice RH. 2007. Arsenite and insulin exhibit opposing effects on epidermal growth factor receptor and keratinocyte proliferative potential. Toxicol Appl Pharmacol. 221(1):119–128. 10.1016/j.taap.2007.02.003 17400267
Pavageau MP, Morin A, Seby F, Guimon C, Krupp E, Pecheyran C, Poulleau J, Donard OF. 2004. Partitioning of metal species during an enriched fuel combustion experiment. speciation in the gaseous and particulate phases. Environ Sci Technol. 38(7):2252–2263. 10.1021/es034408i 15112832
Perez AL, Nembhard M, Monnot A, Bator D, Madonick E, Gaffney SH. 2017. Child and adult exposure and health risk evaluation following the use of metal- and metalloid-containing costume cosmetics sold in the United States. Regulatory toxicology and pharmacology. RTP. 84:54–63. 28007419
Petit de Peña Y, Gallignani M, Burguera M, Burguera JL, Añez N, Lugo A. 1990. Selective determination of antimony (III) and antimony (V) in blood serum and urine by hydride generation and atomic absorption spectrometry. J Braz Chem Soc. 1(2):72–75. 10.5935/0103-5053.19900015
Poon R, Chu I. 2000. Effects of trivalent antimony on human erythrocyte glutathione-S-transferases. J Biochem Mol Toxicol. 14(3):169–176. 10.1002/(SICI)1099-0461(2000)14:3<169::AID-JBT7>3.0.CO;2-L 10711633
PubChem.2017. PubChem Compound Database. Bethesda, MD: National Library of Medicine.https://pubchem.ncbi.nlm.nih.gov/. [Accessed on 6/29/17]
Quiroz W, Aguilar L, Barria M, Veneciano J, Martínez D, Bravo M, Lobos MG, Mercado L. 2013. Sb(V) and Sb(III) distribution in human erythrocytes: Speciation methodology and the influence of temperature, time and anticoagulants. Talanta. 115:902–910. 10.1016/j.talanta.2013.06.052 24054681
Quiroz W, Arias H, Bravo M, Pinto M, Lobos MG, Cortés M. 2011. Development of analytical method for determination of Sb(V), Sb(III) and TMSb(V) in occupationally exposed human urine samples by HPLC-HG-AFS. Microchem J. 97(1):78–84. 10.1016/j.microc.2010.06.015
Quiroz W, De Gregori I, Basilio P, Bravo M, Pinto M, Lobos MG. 2009. Heavy weight vehicle traffic and its relationship with antimony content in human blood. J Environ Monit. 11(5):1051–1055. 10.1039/b815838j 19436864
Ragaini RC, Ralston HR, Roberts N. 1977. Environmental metal contamination in Kellogg, Idaho, near a lead smelting complex. Environ Sci Technol. 11:773–781. 10.1021/es60131a004
Ribeiro RR, Ferreira WA, Martins PS, Neto RL, Rocha OG, Le Moyec L, Demicheli C, Frézard F. 2010. Prolonged absorption of antimony(V) by the oral route from non-inclusion meglumine antimoniate-beta-cyclodextrin conjugates. Biopharm Drug Dispos. 31(2-3):109–119. 20014042
Roper AJ, Williams PA, Filella M. 2012. Secondary antimony minerals: Phases that control the dispersion of antimony in the supergene zone. Chemie der Erde - Geochemistry. 72:9-14. 10.1016/j.chemer.2012.01.005
Salisbury S.1980. Health Hazard Evaluation. St. Clair Rubber Company, Marysville, Michigan. Cincinnati, OH: National Institute for Occupational Safety and Health. HE 79-075-784
Schaumlöffel N, Gebel T. 1998. Heterogeneity of the DNA damage provoked by antimony and arsenic. Mutagenesis. 13(3):281–286. 10.1093/mutage/13.3.281 9643588
Schnorr TM, Steenland K, Thun MJ, Rinsky RA. 1995. Mortality in a cohort of antimony smelter workers. Am J Ind Med. 27(5):759–770. 10.1002/ajim.4700270510 7611310
Schroeder HA, Mitchener M, Balassa JJ, Kanisawa M, Nason AP. 1968. Zirconium, niobium, antimony and fluorine in mice: Effects on growth, survival and tissue levels. J Nutr. 95(1):95–101. 10.1093/jn/95.1.95 5653281
Schroeder HA, Mitchener M, Nason AP. 1970. Zirconium, niobium, antimony, vanadium and lead in rats: Life term studies. J Nutr. 100(1):59–68. 10.1093/jn/100.1.59 5412131
Scinicariello F, Buser MC. 2016. Urinary antimony and leukocyte telomere length: An analysis of NHANES 1999-2002. Environ Res. 150:513–518. 10.1016/j.envres.2016.06.044 27423705
Shacklette HT, Boerngen JG. 1984. Element concentration in soils and other surficial materials of the conterminous United States. Alexandria, VA: U.S. Geological Survey. US Geol Surv Prof Pap. •••:1270.
Shiue I, Hristova K. 2014. Higher urinary heavy metal, phthalate and arsenic concentrations accounted for 3-19% of the population attributable risk for high blood pressure: US NHANES, 2009-2012. Hypertens Res. 37(12):1075–1081. 10.1038/hr.2014.121 25077919
Smith MM.White Ma, Wilson HK. 1995. Determination of antimony in urine by solvent extraction and electrothermal atomization atomic absorption spectrometry for the biological monitoring of occupational exposure. J Anal At Spectrom. 10:349-352. 10.1039/ja9951000349
Smith MT, Guyton KZ, Gibbons CF, Fritz JM, Portier CJ, Rusyn I, DeMarini DM, Caldwell JC, Kavlock RJ, Lambert PF, et al. 2016. Key characteristics of carcinogens as a basis for organizing data on mechanisms of carcinogenesis. Environ Health Perspect. 124(6):713–721. 10.1289/ehp.1509912 26600562
Solubility of Things.2018. Levels of solubility. Educating Online.https://www.solubilityofthings.com/levels-of-solubility. [Accessed on 6/29/18]
Stemmer KL.1976. Pharmacology and toxicology of heavy metals: Antimony. Pharmac Ther A. 1:157-160. 10.1016/0362-5478(76)90005-X
Sudhandiran G, Shaha C. 2003. Antimonial-induced increase in intracellular Ca^2+^ through non-selective cation channels in the host and the parasite is responsible for apoptosis of intracellular Leishmania donovani amastigotes. J Biol Chem. 278(27):25120–25132. 10.1074/jbc.M301975200 12707265
Sumino K, Hayakawa K, Shibata T, Kitamura S. 1975. Heavy metals in normal Japanese tissues. Amounts of 15 heavy metals in 30 subjects. Arch Environ Health. 30(10):487–494. 10.1080/00039896.1975.10666759 1180571
Sunderman FW Jr. 1984. Carcinogenicity of nickel compounds in animals. IARC Sci Publ. 53:127–142. 6532978
Sunderman FW Jr, McCully KS. 1983. Carcinogenesis tests of nickel arsenides, nickel antimonide, and nickel telluride in rats. Cancer Invest. 1(6):469–474. 10.3109/07357908309020271 6667417
Sunderman FW Jr, McCully KS, Hopfer SM. 1984. Association between erythrocytosis and renal cancers in rats following intrarenal injection of nickel compounds. Carcinogenesis. 5(11):1511–1517. 10.1093/carcin/5.11.1511 6488475
Surveillance Epidemiology End Results Program.2018. Surveillance, epidemiology, and end results program. National Institutes of Health, National Institutes of Cancer.https://seer.cancer.gov/. [Accessed on 6/29/18]
T. N. O. Quality of Life. 2005. A study on the biodistribution of antimony trioxide (Sb2O3) in rats. TNO Rep. 6502:1–63.
Takahashi S, Okayasu R, Sato H, Kubota Y, Bedford JS. 2002. Inhibition of radiation-induced DNA-double strand break repair by various metal/metalloid compounds. In: Sugahara T, Nikaido O, Niwa O, editors. Radiation and Homeostasis, Proceedings. Amsterdam: Elsevier Science Bv; p. 327–330. 10.1016/S0531-5131(01)00877-9
Takahashi Y, Sakuma K, Itai T, Zheng G, Mitsunobu S. 2008. Speciation of antimony in PET bottles produced in Japan and China by X-ray absorption fine structure spectroscopy. Environ Sci Technol. 42(24):9045–9050. 10.1021/es802073x 19174869
Tellez-Plaza M, Tang WY, Shang Y, Umans JG, Francesconi KA, Goessler W, Ledesma M, Leon M, Laclaustra M, Pollak J, et al. 2014. Association of global DNA methylation and global DNA hydroxymethylation with metals and other exposures in human blood DNA samples. Environ Health Perspect. 122(9):946–954. 10.1289/ehp.1306674 24769358
Thomas RG, Felicetti SW, Lucchino RV, McClellan RO. 1973. Retention patterns of antimony in mice following inhalation of particles formed at different temperatures. Proc Soc Exp Biol Med. 144(2):544–550. 10.3181/00379727-144-37632 4746928
Tice RR, Austin CP, Kavlock RJ, Bucher JR. 2013. Improving the human hazard characterization of chemicals: A Tox21 update. Environ Health Perspect. 121(7):756–765. 10.1289/ehp.1205784 23603828
Tielemans E, Kupper LL, Kromhout H, Heederik D, Houba R. 1998. Individual-based and group-based occupational exposure assessment: Some equations to evaluate different strategies. Ann Occup Hyg. 42(2):115–119. 10.1016/S0003-4878(97)00051-3 9559571
Tirmenstein MA, Mathias PI, Snawder JE, Wey HE, Toraason M. 1997. Antimony-induced alterations in thiol homeostasis and adenine nucleotide status in cultured cardiac myocytes. Toxicology. 119(3):203–211. 10.1016/S0300-483X(97)03628-7 9152016
Tirmenstein MA, Plews PI, Walker CV, Woolery MD, Wey HE, Toraason MA. 1995. Antimony-induced oxidative stress and toxicity in cultured cardiac myocytes. Toxicol Appl Pharmacol. 130(1):41–47. 10.1006/taap.1995.1006 7839369
Toxics Resealse Inventory Program.2016. TRI Explorer Chemical report. On-site disposal to Class I underground injection wells, RCRA Subtitle C Landfills, and Other Landfills. U.S. Environmental Protection Agency.https://www.epa.gov/triexplorer. [Accessed on 8/18/16]
Tran CL, Buchanan D, Cullen RT, Searl A, Jones AD, Donaldson K. 2000. Inhalation of poorly soluble particles. II. Influence of particle surface area on inflammation and clearance. Inhal Toxicol. 12(12):1113–1126. 10.1080/08958370050166796 11114784
Turner A, Filella M. 2017. Field-portable-XRF reveals the ubiquity of antimony in plastic consumer products. Sci Total Environ. 584-585:982–989. 10.1016/j.scitotenv.2017.01.149 28190576
Turner A, Kearl ER, Solman KR. 2016. Lead and other toxic metals in playground paints from South West England. Sci Total Environ. 544:460–466. 10.1016/j.scitotenv.2015.11.078 26657391
Tylenda CA, Fowler BA.2015. Antimony. In: Nordberg GF, Fowler BA, Nordberg M, editors. Handbook on the Toxicology of Metals. 4th ed. ed. Waltham, MA: Elsevier. p. 565-579.
Tyrrell J, Melzer D, Henley W, Galloway TS, Osborne NJ. 2013. Associations between socioeconomic status and environmental toxicant concentrations in adults in the USA: NHANES 2001-2010. Environ Int. 59:328–335. 10.1016/j.envint.2013.06.017 23892225
Ulrich N. 1998. Speciation of antimony(III), antimony(V) and trimethylstiboxide by ion chromatography with inductively coupled plasma atomic emission spectrometric and mass spectrometric detection. Anal Chim Acta. 359(3):245–253. 10.1016/S0003-2670(97)00656-9
U.S. Environmental Protection Agency (USEPA).1988. Health effects test guidelines: OPPTS 870.3465 90-Day inhalation toxicity. Washington, DC: U.S. Environmental Protection Agency. EPA 712–C–98–204.https://www.regulations.gov/document?D=EPA-HQ-OPPT-2009-0156-0014.
U.S. Environmental Protection Agency (USEPA).2012. Chemical Data Reporting.https://java.epa.gov/oppt_chemical_search/. [Accessed on 3/28/16]
U.S. Environmental Protection Agency (USEPA).2014. TSCA Work Plan Chemical Risk Assessment. Antimony Trioxide. U.S. Environmental Protection Agency. EPA Document # 740‐Z1‐4001
U.S. Environmental Protection Agency (USEPA).2017a. ChemView. U.S. Environmental Protection Agency.https://java.epa.gov/chemview. [Accessed on 2/22/17]
U.S. Environmental Protection Agency (USEPA).2017b. EPA CompTox Chemistry Dashboad. U.S. Environmental Protection Agency.https://comptox.epa.gov/dashboard/. [Accessed on 5/8/18]
U.S. Environmental Protection Agency (USEPA).2017c. iCSS ToxCast Dashboard. Washington, DC: U.S. Environmental Protection Agency.https://actor.epa.gov/dashboard/.
U.S. Geological Survey.2018. Mineral Commodity Summaries, January 2018. Antimony. U.S. Department of Interior, U.S. Geological Survey.https://minerals.usgs.gov/minerals/pubs/commodity/antimony/mcs-2018-antim.pdf.
U.S. International Trade Commission.2017. USITC Interactive Tariff and Trade Dataweb. United States International Trade Commission.https://dataweb.usitc.gov/scripts/user_set.asp. [Accessed on 8/22/17]
Vanoeteren C, Cornelis R, Dams R. 1986 a. Evaluation of trace elements in human lung tissue. II. Recovery and analysis of inhaled particulates. Sci Total Environ. 54:231–236. 10.1016/0048-9697(86)90268-8 3810129
Vanoeteren C, Cornelis R, Verbeeck P. 1986 b. Evaluation of trace elements in human lung tissue. III. Correspondence analysis. Sci Total Environ. 54:237–245. 10.1016/0048-9697(86)90269-X 3810130
Vanoeteren C, Cornelis R, Versieck J. 1986 c. Evaluation of trace elements in human lung tissue. I. Concentration and distribution. Sci Total Environ. 54:217–230. 10.1016/0048-9697(86)90267-6 3810128
Vinas P, López-García I, Merino-Meroño B, Hernández-Córdoba M. 2006. Liquid chromatography-hydride generation-atomic fluorescence spectrometry hybridation for antimony speciation in environmental samples. Talanta. 68(4):1401–1405. 10.1016/j.talanta.2005.07.056 18970479
Wang B, Yu W, Guo J, Jiang X, Lu W, Liu M, Pang X. 2015. The antiparasitic drug, potassium antimony tartrate, inhibits tumor angiogenesis and tumor growth in nonsmall-cell lung cancer. J Pharmacol Exp Ther. 352(1):129–138. 10.1124/jpet.114.218644 25352499
Watt WD.1983. Chronic inhalation toxicity of antimony trioxide: Validation of the threhold limit value. Detroit, MI: Wayne State University, PhD Thesis.
Westrick ML. 1953. Physiologic responses attending administration of antimony, alone or with simultaneous injections of thyroxin. Proc Soc Exp Biol Med. 82(1):56–60. 10.3181/00379727-82-20022 13037801
Whaley P, Halsall C, Agerstrand M, Aiassa E, Benford D, Bilotta G, Coggon D, Collins C, Dempsey C, Duarte-Davidson R, et al. 2016. Implementing systematic review techniques in chemical risk assessment: Challenges, opportunities and recommendations. Environ Int. 92-93:556–564. 10.1016/j.envint.2015.11.002 26687863
Whitworth KW, Han I, Afshar M, Mei Y, Berens PD, Sharma SV, Symanski E. 2017. Accessing disadvantaged pregnant women in Houston, Texas, and characterizing biomarkers of metal exposure: A feasibility study. Int J Environ Res Public Health. 14(5):474. 10.3390/ijerph14050474 28468266
Wingren G, Axelson O. 1985. Mortality pattern in a glass producing area in SE Sweden. Br J Ind Med. 42(6):411–414. 10.1136/oem.42.6.411 4005195
Wingren G, Axelson O. 1993. Epidemiologic studies of occupational cancer as related to complex mixtures of trace elements in the art glass industry. Scand J Work Environ Health. 19 Suppl 1:95–100. 8159983
Witte T, Plass C, Gerhauser C. 2014. Pan-cancer patterns of DNA methylation. Genome Med. 6(8):66. 10.1186/s13073-014-0066-6 25473433
Wortmann GW, Aronson NE, Byrd JC, Grever MR, Oster CN. 1998. Herpes zoster and lymphopenia associated with sodium stibogluconate therapy for cutaneous leishmaniasis. Clin Infect Dis. 27(3):509–512. 10.1086/514689 9770149
Wyllie S, Fairlamb AH. 2006. Differential toxicity of antimonial compounds and their effects on glutathione homeostasis in a human leukaemia monocyte cell line. Biochem Pharmacol. 71(3):257–267. 10.1016/j.bcp.2005.10.043 16318845
Wysocki R, Tamas MJ. 2010. How Saccharomyces cerevisiae copes with toxic metals and metalloids. FEMS Microbiol Rev. 34(6):925–951. 10.1111/j.1574-6976.2010.00217.x 20374295
Xiong J, Liu X, Cheng QY, Xiao S, Xia LX, Yuan BF, Feng YQ. 2017. Heavy metals induce decline of derivatives of 5-methycytosine in both DNA and RNA of stem cells. ACS Chem Biol. 12(6):1636–1643. 10.1021/acschembio.7b00170 28448110
Yamamoto A, Kohyama Y, Hanawa T. 2002. Mutagenicity evaluation of forty-one metal salts by the umu test. J Biomed Mater Res. 59(1):176–183. 10.1002/jbm.1231 11745551
Yi T, Pathak MK, Lindner DJ, Ketterer ME, Farver C, Borden EC. 2002. Anticancer activity of sodium stibogluconate in synergy with IFNs. Journal of immunology (Baltimore, Md: 1950). 169(10):5978-5985. 10.4049/jimmunol.169.10.5978
Young M. 1979 a. Walk-through Survey Report of General Battery and Ceramic Corporation, Dallas, Texas. Cincinnati, OH: Division of Surveillance, Hazard Evaluations, and Field Studies, Industry-wide Studies Branch, Industrial Hygiene Section, National Institute for Occupational Safety and Health.
Young M. 1979 b. Walk-through Survey Report of Standard Industries, Inc. (Reliable Battery Company), San Antonio, Texas. Cincinnati, OH: Division of Surveillance, Hazard Evaluations, and Field Studies, Industry-wide Studies Branch, Industrial Hygiene Section, National Institute for Occupational Safety and Health.
Zhang J, Billiet J, Dams R. 1985. Elemental composition and source investigation of particulates suspended in the air of an iron foundry. Sci Total Environ. 41:13–28. 10.1016/0048-9697(85)90158-5
Zheng FY, Qian SH, Li SX, Huang XQ, Lin LX. 2006. Speciation of antimony by preconcentration of Sb(III) and Sb(V) in water samples onto nanometer-size titanium dioxide and selective determination by flow injection-hydride generation-atomic absorption spectrometry. Anal Sci. 22(10):1319–1322. 10.2116/analsci.22.1319 17038769
Zheng G, Zhong H, Guo Z, Wu Z, Zhang H, Wang C, Zhou Y, Zuo Z. 2014. Levels of heavy metals and trace elements in umbilical cord blood and the risk of adverse pregnancy outcomes: A population-based study. Biol Trace Elem Res. 160(3):437–444. 10.1007/s12011-014-0057-x 25008990
Zhu H, Wang N, Zhang Y, Wu Q, Chen R, Gao J, Chang P, Liu Q, Fan T, Li J, et al. 2010. Element contents in organs and tissues of Chinese adult men. Health Phys. 98(1):61–73. 10.1097/HP.0b013e3181bad921 19959952