# Erratum

An error was identified in the Report on Carcinogens Monograph on Antimony Trioxide. The time to steady state for the 30 mg/m^3^ exposure level has been corrected to 1,310 in this document. [September 9, 2021]