# Appendix F Other Relevant Information

## F.1 Studies of Antimony(III) Potassium Tartrate Carcinogenicity in Experimental Animals

This appendix includes neoplasms induced in experimental animals exposed to antimony potassium tartrate (Table F-1), details of these animal studies (Table F-2) and risk of bias rating of Schroeder et al. (1970) study (Table F-3) and Kanisawa and Schroeder (1969) study (Table F-4).

Table F-1 Neoplasms Induced in Experimental Animal Carcinogenicity Studies by Drinking Water Studies of Antimony Potassium Tartrate

Species Strain/Stock | Site | Classification | Neoplasms (Sex of Animal) | Reference
Rat, Long-Evans | None | None | None (M and F) | Schroeder et al. (1970)
Mouse, Swiss CD-1 | None | None | None (M and F) | Kanisawa and Schroeder (1969); Schroeder et al. (1968)

Studies are presented in the order of descending overall utility.

F = female, M = male.

Table F-2 Cancer Studies in Experimental Animals Exposed to Antimony(III) Potassium Tartrate

Reference and Study Design | Exposure | Tumor Site – Tumor Type | | Comments
Reference and Study Design | Exposure | Dose Levels | Tumor Incidence (n/N) (%) | Comments
Schroeder et al. (1970) Animal: Rat – Long-Evans (random bred) M, F Animal age at the beginning of exposure: NR (possibly at weaning) Study duration: ~4 years | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 ppm not clearly reported (possibly ad libitum × life span) | Whole body – Tumor NOS (M) | | Survival: The survival of females at 50% death (p < 0.025 by chi-square analysis) and males and females for longevity (mean age of the last surviving 10%) (p < 0.001 by Student’s t test) was significantly reduced compared to untreated controls. Body weight: Both males and females were similar to controls. Overall utility: [+] The study has low utility because of many limitations, including only reporting grossly visible tumors without organ site or tumor type.
Schroeder et al. (1970) Animal: Rat – Long-Evans (random bred) M, F Animal age at the beginning of exposure: NR (possibly at weaning) Study duration: ~4 years | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 ppm not clearly reported (possibly ad libitum × life span) | 0 | 10/50 (20%)
Schroeder et al. (1970) Animal: Rat – Long-Evans (random bred) M, F Animal age at the beginning of exposure: NR (possibly at weaning) Study duration: ~4 years | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 ppm not clearly reported (possibly ad libitum × life span) | 5 | 6/50 (12%)
Schroeder et al. (1970) Animal: Rat – Long-Evans (random bred) M, F Animal age at the beginning of exposure: NR (possibly at weaning) Study duration: ~4 years | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 ppm not clearly reported (possibly ad libitum × life span) | Whole body – Tumor NOS (F)
Schroeder et al. (1970) Animal: Rat – Long-Evans (random bred) M, F Animal age at the beginning of exposure: NR (possibly at weaning) Study duration: ~4 years | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 ppm not clearly reported (possibly ad libitum × life span) | 0 | 14/39 (35.9%)
Schroeder et al. (1970) Animal: Rat – Long-Evans (random bred) M, F Animal age at the beginning of exposure: NR (possibly at weaning) Study duration: ~4 years | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 ppm not clearly reported (possibly ad libitum × life span) | 5 | 18/47 (38.3%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | Whole body – Tumor NOS | | Survival: Survival was similar to controls. Body weight: Males were sporadically lower than controls at 90, 150, and 540 days, while females were more consistently lower at 150, 360, and 540 days. Other comments: The incidences were reported for both sexes combined, but it was stated that none of the neoplasms were significantly increased. Overall utility: [+] This study is of low utility due to many limitations, including only one tested concentration (below maximally tolerated dose for males, and close to or at maximally tolerated dose for females), unknown test substance purity, tumor incidences only reported in combined sexes with no histologic information, and lack of site-specific information (except incidences of three sites in sexes combined). Data lack sufficient details to allow us to determine whether any specific type of tumor had increased in a sex.
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 0 | 24/71 (33.8%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 5 | 18/76 (23.7%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | Whole body – Malignant tumor NOS
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 0 | 8/71 (11.3%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 5 | 6/76 (7.9%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | Whole body – Benign tumor NOS
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 0 | 16/71 (22.5%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 5 | 12/76 (15.8%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | Mammary gland – Tumor NOS
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 0 | 1/71 (1.4%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 5 | 3/76 (3.9%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | Lung – Tumor NOS
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 0 | 15/71 (21.1%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 5 | 10/76 (13.2%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | Liver – Tumor NOS
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 0 | 4/71 (5.6%)
Kanisawa and Schroeder (1969) Animal: Mouse – White Swiss CD-1 (Random bred) M+F (combined) Animal age at the beginning of exposure: Weanling Study duration: Life span | Agent and purity: Antimony potassium tartrate NR Exposure route: Drinking water Exposure concentrations, frequency, and duration: 0 5 μg/mL in double deionized water ad libitum × life span | 5 | 1/76 (1.3%)

F = female; M = male; n/N = number of animals with neoplasms divided by the total number of animals tested in that dose group; NR = not reported; NOS = not otherwise specified.

Table F-3 Schroeder et al. (1970) Study of Male Rats and Female Rats Exposed to Antimony(III) Potassium Tartrate in Drinking Water for the Life Span of the Animals

Utility Question | Rating | Rationale
Study design
Randomization | NR | Randomization and initial body weights were not reported.
Controls | +++ | Concurrent control group, exposed to untreated drinking water, had the same number of animals as exposure group did.
Historical data | | No
Animal model | +++ | Both sexes of a random bred strain, which increases external validity.
Statistical power | +++ | Large numbers of animals (51 males, 59 females) per concentration group were used.
Exposure
Chemical characterization | NR | Not reported, not even purity.
Dosing regimen | ++ | The maximally tolerated dose level was not reached, because the treated group did not show decreased body weight compared to the control group, although the median life spans and longevity (mean age of the last surviving 10%) for both sexes were decreased by the treatment. The dose might not have been high enough to detect neoplastic effects.
Exposure duration | +++ | Though exposure duration was never clearly stated, this study appears to use a lifetime exposure.
Dose-response | + | Only one dose level was tested and no basis for that level was reported. All other elements were administered at the same level, except for lead.
Outcome
Pathology | + | Only grossly visible tumors were reported. The methods stated that gross tumors were fixed but did not state that they were stained or microscopically examined. Consequently, small tumors might have been missed.
Consistency between groups | ++ | A pneumonia epidemic killed many rats and the death rates varied among the groups.
Study duration | +++ | Lifetime study because the animals were observed until their natural death (as compared to scheduled euthanization after a predetermined exposure period).
Confounding
Confounding | ++ | Pneumonia killed various numbers of animals per group, before penicillin treatment controlled the disease. It is unclear that all rats, or only visibly sick rats, received penicillin. Furthermore, the disease might in effect select stronger/healthier animals (than the general population) to complete the study. Additionally, test substance purity was unknown.
Reporting and analysis
Reporting data and statistics | ++ | The statistical methods and results of survival measures were reported, but a statistical analysis of tumor incidences was not reported.
Combining lesions | + | Tumors were counted based on gross observation, not histological analysis occurred.

Overall utility: +. The study has low utility because of many limitations, including only reporting grossly visible tumors without organ site or tumor type.

NR = not reported; +++ = high utility; ++ = moderate utility; + = low utility.

Table F-4 Kanisawa and Schroeder (1969) Study of Male and Female (Combined) Mice Exposed to Antimony Potassium Tartrate in Drinking Water for the Life Span of the Animals

Utility Question | Rating | Rationale
Study design
Randomization | NR | Not reported.
Controls | +++ | Concurrent control group, exposed to doubly deionized water with added essential trace elements, had the same number of animals as the exposure group did.
Historical data | | No
Animal model | +++ | Both sexes of random bred mice were used, giving a high level of external validity.
Statistical power | +++ | A large number (54) of mice per sex per group were used.
Exposure
Chemical characterization | NR | No chemical characterization was reported, not even purity.
Dosing regimen | + | The maximally tolerated dose level was not reached, because the treated group did not show decreased body weight compared to the control group. The dose might not have been high enough to detect neoplastic effects.
Exposure duration | +++ | Mice were exposed for their lifetimes.
Dose-response | + | Only one concentration was tested and no rational for the dose selection was reported. Dose response relationships cannot be evaluated due to only one dose level.
Outcome
Pathology | ++ | Only gross lesions were microscopically evaluated.
Consistency between groups | ++ | The treated and control groups were treated the same while mice were alive. The examination of organs/tissues varied, because only gross lesions (not all major organs) were examined microscopically.
Study duration | +++ | The study duration was lifetime, up to the animals' natural death.
Confounding
Confounding | +++ | Testing substance purity and supplier were unknown. Exposure to antimony via other sources (feed, housing) was negligible because the feed was antimony free and metal exposure via housing was minimized.
Reporting and analysis
Reporting data and statistics | ++ | Although tumor incidents were not statistically analyzed in the study, the data were reported and enabled us to conduct statistical analysis. Statistical methods were described as “numerical data were treated by Chi-squire analysis and by Student’s t test,” but the reported probability in tables did not specify the result was from which method.
Combining lesions | ++ | Tumor incidence was reported for two sexes combined only, instead of male and female separately. Site-specific (lung, liver, mammary gland, and other) information was limited to tumor incidence, with no subtype. Tumors were also grouped by origin (epithelial, non-epithelial) along with being benign or malignant. Overall information did not allow detecting of specific tumor type increase in either sex.

Overall utility: +. Due to many limitations, including only one tested concentration (below maximally tolerated dose), unknown test substance purity, tumor incidences only reported in combined sexes with no histologic information, and lack of site-specific information (except incidences of three sites in sexes combined), this study is of low utility. Data lack sufficient details to allow us to determine whether any specific type of tumor had increased.

NR = not reported; +++ = high utility; ++ = moderate utility; + = low utility.