# Appendix E Mechanistic and Other Relevant Information

This appendix lists Tox21/ToxCast high-throughput screening (Appendix E.1), effects of antioxidant and inhibitors of enzymes on antimony effects (Appendix E.2), genotoxicities of antimony compounds (Appendix E.3), effects related to cell proliferation (Appendix E.4), transcriptomic of antimony(III) potassium tartrate trihydrate in HepG2 cells (Appendix E.5), and immune effects of compounds containing pentavalent antimony (Appendix E.6).

## E.1 Tox21/ToxCast High-throughput Screening

A total of six antimony compounds, not including antimony(III) trioxide, were found in the Tox21 (Tice et al. 2013) and ToxCast (Kavlock et al. 2012; Kavlock and Dix 2010) results from the Tox21 Toolbox (NTP 2017c) and iCSS Dashboard (USEPA 2017c): (1) acetic acid, antimony(III) salt, (2) antimony potassium(III) tartrate trihydrate, (3) antimony(III) trichloride, (4) antimony(V) sulfide, (5) antimony(III) potassium tartrate hydrate, and (6) triphenylstibine(III).

All of the above antimony compounds except acetic acid, antimony(III) salt and antimony potassium(III) tartrate trihydrate were screened in some of the Tox21 assays, although the assays varied. Among the antimony compounds screened in Tox21, triphenylstibine(III) was also screened in ToxCast in only some of the assays in the Attagene (ATG), CeeTox, and NovaScreen (NVS) platforms. In addition, antimony(III) trichloride was also screened in the ATG platform and three estrogen receptor assays in the NVS platform in ToxCast.

The data are reviewed for antimony compounds screened in the subset of assays (Chiu et al. 2017; IARC 2017b) that relate to the 10 key characteristics of human carcinogens (Smith et al. 2016). For the purpose of comparing different antimony compounds, only the responses from Tox21 assays, in which several antimony compounds were tested, were compared. The half maximal effective concentration (EC_50_) and weighted area under the curve were obtained from the Tox21 Toolbox Activity Profiler. Assay results exhibiting the following characteristics were excluded from the analysis: observed cytotoxicity, autofluorescence, insufficient reporter gene activity readout support, suboptimal National Center for Advancing Translational Sciences fits, or substantial variation between sources. Assays that assessed only cell viability were not included. All effective EC_50_s were within an order of magnitude. Please note that analysis via different criteria, such as dose-response fit threshold, will result in different hits, and therefore the results shown here might be different from others.

The only pentavalent antimony compound, antimony(V) sulfide, showed no activity in Tox21 assays. Antimony(III) potassium tartrate hydrate was active only in one androgen receptor antagonist assay, which was also activated by antimony(III) potassium tartrate trihydrate. Triphenylstibine was not active in any assays linked with the 10 key characteristics of carcinogens, but was active in assays associated with nuclear receptors, including constitutive androstane receptor, pregnane X receptor, and retinoic acid-related orphan receptors γ.

Antimony(III) trichloride and antimony(III) potassium tartrate trihydrate had hits in more assays than other screened antimony compounds. Observed hits by both were related to oxidative stress or antagonism of nuclear receptors, including the androgen receptor, farnesoid X receptor, and peroxisome proliferator-activated receptor delta. Antimony(III) potassium tartrate trihydrate was also active in an estrogen receptor antagonist assay. One of the common characteristics of nuclear receptors is DNA-binding domain or zinc finger structure. Antimony(III) ions have been reported to displace Zn(II) in zinc finger domains (Grosskopf et al. 2010; Nielson et al. 1985), providing a possible link to the observed antagonist activity of nuclear receptors.

In summary, the activities of antimony compounds in Tox21 assays were mostly antagonistic to nuclear receptors, possibly because of displacement of Zn(II) in the zinc finger structures of these receptors by antimony(III) ions. These assays also indicated an oxidative stress response. Because only one antimony(V) compound was screened, and some of the trivalent compounds had very little activity in the Tox21 assays, it is unclear whether antimony(III) compounds are in general more active than antimony(V) compounds.

## E.2 Effects of Antioxidants and Inhibitors of Oxidative Stress Related Enzymes on Cells Exposed to Compounds Containing Trivalent Antimony

Table E-1 Effects of Antioxidants and Inhibitors of Oxidative Stress Related Enzymes on Cells Exposed to Compounds Containing Trivalent Antimony

Cell Types | Additional Treatment (Besides Antimony Exposure) | Oxidative Stress and Damage | MMP and Cell Death | Comparison Group (Cells) | Reference
Antimony (III) trioxide
LOUCY, CCRF-CEM, HL-60, K-562 | BSO, an inhibitor of γ-glutamylcysteine synthetase | ↓ GSH | ↓ MMP^a^ ↑ cell death | exposed to Sb_2_O_3_ alone | Lösler et al. (2009)
HL-60, K-562 | Mercaptosuccinic acid, an inhibitor of glutathione peroxidase | | ↑ cell death | exposed to Sb_2_O_3_ alone | Lösler et al. (2009)
K-562 | 3-amino-1,2,4-azole, an inhibitor of catalase | | ↑ cell death | exposed to Sb_2_O_3_ alone | Lösler et al. (2009)
CCRF-CEM, K-562 | Sodium ascorbate, an antioxidant, but able to act as an oxidant under oxidative stress | | ↑ cell death | exposed to Sb_2_O_3_ alone | Lösler et al. (2009)
NB4 | None | ↑ ROS | ↑ cell death | negative control | Mann et al. (2006)
NB4-M-AsR3 | None | ↑ GSH | ↓ cell death | parental NB4 cells | Mann et al. (2006)
NB4 | BSO, an inhibitor of γ-glutamylcysteine synthetase | ↓ GSH ↑ ROS | ↑ cell death | cells not treated with BSO | Mann et al. (2006)
NB4-M-AsR3 | BSO, an inhibitor of γ-glutamylcysteine synthetase | ↓ GSH | ↑ cell death | cells not treated with BSO | Mann et al. (2006)
Antimony (III) trichloride
Primary rat hepatocytes | none | ↑ ROS ↑ lipid peroxidation | ↓ MMP ↑ cell death | – | Hashemzaei et al. (2015)
Primary rat hepatocytes | n-bromoheptane, a GSH-depleting agent | ↓ GSH- ↑ ROS ↑ lipid peroxidation | ↓ MMP ↑ cell death | exposed to SbCl_3_ alone | Hashemzaei et al. (2015)
Primary rat hepatocytes | Dimethyl sulfoxide, a ROS scavenger | ↓ ROS ↓ lipid peroxidation | ↑ MMP ↑ cell death | exposed to SbCl_3_ alone | Hashemzaei et al. (2015)
Primary rat hepatocytes | Mannitol, a ROS scavenger | ↓ ROS ↓ lipid peroxidation | ↑ MMP ↓cell death | exposed to SbCl_3_ alone | Hashemzaei et al. (2015)
Primary rat hepatocytes | Trifluoperazine, a mitochondria permeability transition pore sealing agent | ↓ ROS ↓ lipid peroxidation | ↑ MMP ↑ cell death | exposed to SbCl_3_ alone | Hashemzaei et al. (2015)
Primary rat hepatocytes | Carnitine, a mitochondria permeability transition pore sealing agent | ↓ ROS ↓ lipid peroxidation | ↑ MMP ↓cell death | exposed to SbCl_3_ alone | Hashemzaei et al. (2015)
Primary rat hepatocytes | L-Glutamine, an adenosine triphosphate (ATP) generating agent | ↓ ROS ↓ lipid peroxidation | ↑ MMP ↑ cell death | exposed to SbCl_3_ alone | Hashemzaei et al. (2015)
Antimony (III) potassium tartrate
HL-60 | none | ↑ ROS | ↓ MMP ↑ cell death | negative control | Lecureur et al. (2002)
HL-60 | BSO | – | ↑ cell death | exposed to antimony alone | Lecureur et al. (2002)
HL-60 | N-acetylcysteine | – | ↓ cell death | exposed to antimony alone | Lecureur et al. (2002)

↑ = increased; ↓ = decreased; NB4-M-AsR3 = arsenic-resistant subclone of parental NB4 due to increased GSH levels; BSO = DL-buthionine-[S,R]-sulfoximine; CCRF-CEM = a cell line derived from acute lymphoblastic leukemia cells; HL-60 = a cell line derived from human promyelocytic leukemia; K-562 = chronic myelogenous leukemia cells; LOUCY = a cell line derived from T cell acute lymphoblastic leukemia; MMP = mitochondrial membrane potential; NB4 = a cell line derived from human acute promyelocytic leukemia cells; NB4-M-AsR3 cells = arsenic-resistant APL cells (derived in Miller lab).

## E.3 Genotoxicity Tables

The genotoxic tables are organized by endpoints: mutations (Table E-2), DNA damage (Table E-3), chromosomal aberrations (Table E-4).

Table E-2 Genotoxicity of Antimony Compounds: Mutations^a^

Genotoxicity Endpoint | Antimony Form | Testing System/Exposure Duration | Assay Endpoint | Comments | Reference
Mammalian cells
Point mutations and chromosome deletions | Antimony trioxide | L5178Y mouse lymphoma cell line (+/−S9, two experiments) 4-hour exposure duration | Negative (concentrations tested: 6–50 μg/mL) | Precipitate formed at top dose level; authors report no significant toxicity at these doses | Elliott et al. (1998)
Bacteria
A/T base pair substitutions | Antimony trioxide | E. coli B/r WP2 try and WP2 hcr try (−S9, spot test method) | Negative (concentrations tested: 0.05–0.5 M) | Microbial toxicity not reported | Kanematsu et al. (1980)
A/T base pair substitution | Antimony trioxide | E. coli WP2P (+/−S9; plate incorporation and pre-incubation protocols) 3-day exposure duration | Negative (concentrations tested: 100–5,000 μg/plate) | Microbial toxicity not reported | Elliott et al. (1998)
A/T base pair substitution | Antimony trioxide | E. coli WP2PuvrA (+/−S9; plate incorporation and pre-incubation protocols) 3-day exposure duration | Negative (concentrations tested: 100–5,000 μg/plate) | – | Elliott et al. (1998)
A/T base pair substitutions | Antimony trichloride | E. coli B/r WP2 try and WP2 hcr try (−S9, spot test method) | Negative (concentrations tested: 0.05–0.5 M) | Microbial toxicity not reported | Kanematsu et al. (1980)
G/C base pair substitutions | Antimony trioxide | S. typhimurium TA 1535, TA 1537, TA100, TA98 (+/−S9; plate incorporation and pre-incubation protocols) 3-day exposure duration | Negative (concentrations tested: 100–5,000 μg/plate) | Microbial toxicity not reported | Elliott et al. (1998)
Frameshift mutations | Antimony trioxide | S. typhimurium TA 1537 and 98 (+/−S9; plate incorporation and 60 min pre-incubation protocols) 3-day exposure duration | Negative (concentrations tested: 100–5,000 μg/plate) | Microbial toxicity not reported | Elliott et al. (1998)
Base pair substitution and frameshift mutations | Antimony trioxide | S. typhimurium TA98, TA100, TA1535, TA1537, TA1568 (−S9, spot test method) | Negative (concentrations tested: 0.05–0.5 M) | Duration of chemical exposure for spot test assay not reported; microbial toxicity not reported | Kanematsu et al. (1980)
Base pair substitution and frameshift mutations | Antimony trioxide | S. typhimurium TA100, TA98 (+/−S9; 20 min pre-incubation modification) | Negative in three experiments (concentrations tested: 0.43–1.71 μg/plate) | Survival after pre-incubation step reported | Kuroda et al. (1991)
Base pair substitution and frameshift mutations | Antimony trichloride | S. typhimurium TA98, TA100, TA1535, TA1537, TA1568 (−S9, spot test method) | Negative (concentrations tested: 0.05–0.5 M) | Duration of chemical exposure for spot test assay not reported; microbial toxicity not reported | Kanematsu et al. (1980)
Base pair substitution and frameshift mutations | Antimony trichloride | S. typhimurium TA100, TA98 (+/−S9; 20 min pre-incubation modification) | Negative in three experiments (concentrations tested: 625–5,000 μg/plate) | Survival after pre-incubation step reported | Kuroda et al. (1991)

Levels of significance are designated as follows: *p < 0.05; **p < 0.01.

Mutation studies are listed hierarchically according to the following criteria: (1): by genotoxicity endpoints; (2): by domain of target species (eukaryote and then prokaryote); (3): by testing system (e.g., E. coli strains and then Salmonella strains); and (4): by compound in the order of antimony(III) trioxide (bold) and then antimony(III) trichloride. Other forms of antimony, such as elemental antimony (Asakura et al. 2009) were not included in the table.

^a^ All data in prokaryotes were derived bacterial reverse mutation assays. The single eukaryotic study data was derived from the mouse lymphoma TK gene mutation assay.

Table E-3 Genotoxic DNA Damaging Effects of Antimony Compounds

Genotoxicity Endpoint | Antimony Form | Assay Name | Testing System | Assay Endpoint | | | | Comments | | References
DNA Damage (epidemiological studies)^a^
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | Frequency of subjects with oxidative DNA damage | | | | Sb_2_O_3_ levels for direct and indirect exposure groups lower than OSHA/NIOSH PEL and REL for workplace. Moderate oxidative DNA damage observed in direct exposure group (0.12 ± 0.11 μg/m^3^); potential concomitant exposures not addressed. | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | Conc. (μg/m^3^) | | | # with oxidative damage/total | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0 | | | 3/23 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0.120 ± 0.110 | | | 11/17 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0.052 ± 0.038 | | | 1/6 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | Relative risk of DNA damage | | | | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | Conc. (μg/m^3^) | Adjusted relative risk | | 95% CI | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0 | 1 | | n/a | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0.120 ± 0.110 | 14.2** | | 2.7–73.4 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0.052 ± 0.038 | 1.7 | | 0.1–22.5 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | Tail moment values for FPG-treated cells | | | | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | Conc. (μg/m^3^) | | | Mean ± SD | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0 | | | 24.4 ± 9.51 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0.120 ± 0.110 | | | 32.4 ± 16.3 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0.052 ± 0.038 | | | 28.8 ± 5.61 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | Tail moment values for untreated cells | | | | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | Conc. (μg/m^3^) | | | Mean ± SD | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0 | | | 16.3 ± 6.59 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0.120 ± 0.110 | | | 14.6 ± 8.29 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | Alkaline FPG-modified comet assay | Blood lymphocytes from occupationally exposed workers (−S9) | 0.052 ± 0.038 | | | 18.3 ± 8.78 | | Cavallo et al. (2002)
DNA strand breaks, alkali labile sites, oxidized purines | Occupational antimony trioxide | AP sites quantified using ELISA technique | Blood lymphocytes from occupationally exposed workers (−S9) | The quantity of DNA damage (determined by the number of AP sites/1 × 10^5^ bp) among the studied workers was significantly (p = 0.004) higher compared to that recorded for the control group and a significant positive correlation was found between the quantity of DNA damage (in the form of increased AP sites) and urinary antimony level among workers (r = 0.873, p < 0.001). Total oxidative capacity (also measured by ELISA) was not different between workers and controls. | | | | The number of measured basic sites ranged from 17.22 (control group) to 26.88 (exposed workers)/1 × 10^5^ bp. This range is higher than expected. | El Shanawany et al. (2017)
DNA damage (in vitro studies in human cells)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | Mean tail moment in human whole blood in comet assay without proteinase K | | | | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | Conc. (μM) | Time. (hrs) | | Mean ± SD | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 0 | 2.5 | | 1.28 ± 0.10 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 1 | 2.5 | | 1.26 ± 0.01 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 5 | 2.5 | | 1.32 ± 0.08 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 10 | 2.5 | | 1.32 ± 0.04 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 25 | 2.5 | | 1.47 ± 0.07 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 50 | 2.5 | | 1.75 ± 0.08* | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | Mean tail moment in human lymphocytes in comet assay without proteinase K | | | | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | Conc. (μM) | Time (hrs) | | Mean ± SD | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 0 | 2.5 | | 1.00 ± 0.02 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 1 | 2.5 | | 1.23 ± 0.28 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 5 | 2.5 | | 1.39 ± 0.19* | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 10 | 2.5 | | 1.56 ± 0.04* | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 25 | 2.5 | | 1.64 ± 0.03*** | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 50 | 2.5 | | 2.14 ± 0.01*** | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | Mean tail moment in human lymphocytes in comet assay with proteinase K | | | | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | Conc. (μM) | Time (hrs) | | Mean ± SD | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 0 | 2.5 | | 1.08 ± 0.11 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 1 | 2.5 | | 1.13 ± 0.09 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 5 | 2.5 | | 1.30 ± 0.20 | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 10 | 2.5 | | 1.47 ± 0.13* | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 25 | 2.5 | | 1.53 ± 0.08* | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA strand breaks, alkali labile sites, DNA-protein crosslinks | Antimony trichloride (concentrations tested: 1–50 μM) | Alkaline comet assay +/− proteinase K | Human whole blood or human lymphocytes exposed ex vivo (−S9) | 50 | 2.5 | | 1.94 ± 0.30*** | Significance tested by Kruskal-Wallis one-way ANOVA on ranks. | Schaumlöffel and Gebel (1998)
DNA damage (animal studies)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | | Percent tail DNA | | | | Trend tests show significant increase for both lung tissue of males and females exposed to trioxide; no increase in percent tail DNA observed in leukocytes of males or females exposed to trioxide. Normally distributed data analyzed by independent sample’s t-test and linear regression; data that were not normally distributed were analyzed by the Mann-Whitney test followed by the Kendall rank correlation test. | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | | Dose (mg/m^3^) | Time (mo.) | Mean ± SE | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | | 0 | 12 | 25.6 ± 0.78 | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | | 3 | 12 | 33.7 ± 2.62* | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | | 10 | 12 | 33.5 ± 2.02** | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | | 30 | 12 | 37.5 ± 2.28*** | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | Lung of female mice exposed via inhalation for 12 months | Percent tail DNA | | | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | Lung of female mice exposed via inhalation for 12 months | Dose (mg/m^3^) | Time (mo.) | Mean ± SE | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | Lung of female mice exposed via inhalation for 12 months | 0 | 12 | 32.8 ± 1.11 | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | Lung of female mice exposed via inhalation for 12 months | 3 | 12 | 35.8 ± 2.09 | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | Lung of female mice exposed via inhalation for 12 months | 10 | 12 | 36.4 ± 2.65 | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | Lung of female mice exposed via inhalation for 12 months | 30 | 12 | 45.5 ± 2.32*** | | | NTP (2017a)
DNA strand breaks and alkali labile sites | Antimony trioxide NC: air | In vivo exposure (inhalation) Alkaline comet assay | Lung and blood leukocytes of male and female rats exposed via inhalation for 12 months | No statistically significant increases were observed in percent tail DNA in blood leukocytes or lung tissue in exposed rats of either sex | | | | Normally distributed data analyzed by independent sample’s t-test; data that were not normally distributed were analyzed by the Mann-Whitney test followed by the Kendall rank correlation test. | NTP (2017a)
DNA damage (in vitro studies in non-human mammalian cells)
DNA strand breaks and alkali labile sites | Antimony trichloride | Alkaline comet assay | V79 Chinese hamster cells exposed in vitro (−S9) | Tail moment was significantly elevated at a minimum dose of 1 μM Sb(III); no difference could be found comparing the results obtained in presence and absence of proteinase K. | | | | DNA damage observed below cytotoxic levels; antimony uptake measured. | Gebel et al. (1998)
DNA damage (bacterial systems)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | HI17 (Rec+) and M45 (Rec-) inhibition length | | | | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | Conc. (μg/plate) | | | Difference in Inhibition length (mm) | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | NC (5) | | | 0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | NC (10) | | | 0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | NC (20) | | | 0.5 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | PC (0.05) | | | 8.0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | PC (0.1) | | | 8.0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | PC (0.2) | | | 7.0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | 0.3 | | | 2.5 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | 0.6 | | | 4.0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide NC: Kanamycin (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) | 1.1 | | | 4.5 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide PC and NC: other metals tested | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | HI17 (Rec+) and M45 (Rec-) inhibition length | | | | Examined 127 metals; used streak plate method; included cold incubation step to increase contact of metal with bacteria. | | Kanematsu et al. (1980)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide PC and NC: other metals tested | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | Solution conc. (M) | | | Difference in inhibition length (mm) | Examined 127 metals; used streak plate method; included cold incubation step to increase contact of metal with bacteria. | | Kanematsu et al. (1980)
Growth in recombination-repair deficient bacterial strain | Antimony trioxide PC and NC: other metals tested | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | 0.05 | | | 5 | Examined 127 metals; used streak plate method; included cold incubation step to increase contact of metal with bacteria. | | Kanematsu et al. (1980)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | HI17 (Rec+) and M45 (Rec-) inhibition length | | | | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | Conc. (μg/plate) | | | Difference in inhibition length (mm) | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | NC (5) | | | 0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | NC (10) | | | 0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | NC (20) | | | 0.5 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | PC (0.05) | | | 8.0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | PC (0.1) | | | 8.0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | PC (0.2) | | | 7.0 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | 6.3 | | | 1.5 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | 12.5 | | | 4.5 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride NC: Kanamycln (5, 10 20 μg/plate) PC: Mitomycin C (0.05, 0.1, and 0.2 μg/plate) | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | 23 | | | 4.5 | Used spore plate method. | | Kuroda et al. (1991)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | Antimony trichloride result was negative in rec assay (tested at 0.05 M) | | | | Antimony pentachloride also negative. | | Nishioka (1975)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride PC and NC: other metals tested | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | HI17 (Rec+) and M45 (Rec-) inhibition length | | | | Examined 127 metals; used streak plate method; included cold incubation step to increase contact of metal with bacteria. | | Kanematsu et al. (1980)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride PC and NC: other metals tested | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | Solution Conc. (M) | | | Difference in inhibition length (mm) | Examined 127 metals; used streak plate method; included cold incubation step to increase contact of metal with bacteria. | | Kanematsu et al. (1980)
Growth in recombination-repair deficient bacterial strain | Antimony trichloride PC and NC: other metals tested | B. subtilis rec assay | B. subtilis M45(rec-) and H17(rec+) (−S9) | 0.01 | | | 7 | Examined 127 metals; used streak plate method; included cold incubation step to increase contact of metal with bacteria. | | Kanematsu et al. (1980)
Induction of recombination-repair genes | Antimony trichloride | SOS chromotest for genotoxicity | E. coli PQ37 derived from strain GC4436 (−S9) | SOS chromotest was negative for antimony trichloride (concentration tested: 11–707 μM) | | | | Cytotoxicity observed at 354 μM. | | Lantzsch and Gebel (1997)
Induction of recombination-repair genes | Antimony trichloride | Umu test for genotoxicity | S. typhimurium TA1535/pSK1002 (−S9) | Umu test was negative for antimony trichloride (concentrations tested: 1.6–820 μM) | | | | Data not reported. | | Yamamoto et al. (2002)
DNA Damage (biochemical assay)
Plasmid DNA nicking | Trimethyl-stibine Potassium antimony tartrate PC: Trimethyl-arsine | Plasmid DNA-nicking assay | Plasmid pBR322 exposed in vitro (gaseous phase) to test reactions for 30 min. | Estimated Quantity of Open Circular form of Plasmid^d^ | | | | Chemical reactions to produce trimethylstibine were conducted in situ; plus and minus designations were estimated from images only (no quantitation of nicked and supercoiled forms). Negative results were reported for potassium antimony tartrate. | | Andrewes et al. (2004)
Plasmid DNA nicking | Trimethyl-stibine Potassium antimony tartrate PC: Trimethyl-arsine | Plasmid DNA-nicking assay | Plasmid pBR322 exposed in vitro (gaseous phase) to test reactions for 30 min. | Dose (μM) | | | Result | | | Andrewes et al. (2004)
Plasmid DNA nicking | Trimethyl-stibine Potassium antimony tartrate PC: Trimethyl-arsine | Plasmid DNA-nicking assay | Plasmid pBR322 exposed in vitro (gaseous phase) to test reactions for 30 min. | Trimethyl-stibine | NC | | +/− | | | Andrewes et al. (2004)
Plasmid DNA nicking | Trimethyl-stibine Potassium antimony tartrate PC: Trimethyl-arsine | Plasmid DNA-nicking assay | Plasmid pBR322 exposed in vitro (gaseous phase) to test reactions for 30 min. | Trimethyl-stibine | 5 | | +/− | | | Andrewes et al. (2004)
Plasmid DNA nicking | Trimethyl-stibine Potassium antimony tartrate PC: Trimethyl-arsine | Plasmid DNA-nicking assay | Plasmid pBR322 exposed in vitro (gaseous phase) to test reactions for 30 min. | Trimethyl-stibine | 20 | | +/− | | | Andrewes et al. (2004)
Plasmid DNA nicking | Trimethyl-stibine Potassium antimony tartrate PC: Trimethyl-arsine | Plasmid DNA-nicking assay | Plasmid pBR322 exposed in vitro (gaseous phase) to test reactions for 30 min. | Trimethyl-stibine | 50 | | + | | | Andrewes et al. (2004)
Plasmid DNA nicking | Trimethyl-stibine Potassium antimony tartrate PC: Trimethyl-arsine | Plasmid DNA-nicking assay | Plasmid pBR322 exposed in vitro (gaseous phase) to test reactions for 30 min. | Trimethyl-stibine | 200 | | ++ | | | Andrewes et al. (2004)
Plasmid DNA nicking | Trimethyl-stibine Potassium antimony tartrate PC: Trimethyl-arsine | Plasmid DNA-nicking assay | Plasmid pBR322 exposed in vitro (gaseous phase) to test reactions for 30 min. | Trimethyl-stibine | 500 | | +++ | | | Andrewes et al. (2004)
Plasmid DNA nicking | Trimethyl-stibine Potassium antimony tartrate PC: Trimethyl-arsine | Plasmid DNA-nicking assay | Plasmid pBR322 exposed in vitro (gaseous phase) to test reactions for 30 min. | Trimethyl-stibine | 5,000 | | +++ | | | Andrewes et al. (2004)

Levels of significance are designated as follows: *p < 0.05; **p < 0.01; ***p < 0.001.

Listing order of the studies are as follows: (1): assay, in the order of metaphase analysis, micronucleus assay, and sister chromatid exchange assay; (2): target system, in the order of studies in human cells, animal studies, in vitro studies, and biochemical studies; (3): compound, in the order of antimony(III) trioxide (bold), antimony(III) trichloride, and other antimony(III) compounds.

AP = apurinic/apyrimidinic; avg = average; CI = confidence interval; conc. = concentration; ELISA = enzyme-linked immunosorbent assay; FPG = formamidopyrimidine-DNA glycosylase; hr = hour(s); mo = month(s); NC = negative control; NR = not reported; PC = positive control; SD = standard deviation; SE = standard error; VC = vehicle control.

^a^ DNA damage estimated as quantity of open circular (vs supercoiled) forms from images of plasmids electrophoretically separated in ethidium bromide-stained agarose gels.

Table E-4 Genotoxicity of Antimony Compounds – Chromosomal Aberrations, Micronucleus, and Sister Chromatic Exchange^a,b^

Substance | Exposure and Assay Name | Testing System and Exposure Duration | Assay Endpoint | | | | Comments | References
Chromosomal aberrations
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (−S9) Exposure time: 20 hr and 44 hr Dose: 10, 50, 100 μg/mL | Mean % aberrant cells excluding gaps | | | | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (−S9) Exposure time: 20 hr and 44 hr Dose: 10, 50, 100 μg/mL | Group | HIC/LEC (μg/mL, unless specified) | | Mean (%) | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (−S9) Exposure time: 20 hr and 44 hr Dose: 10, 50, 100 μg/mL | NC | – | | 0.5–1.5 | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (−S9) Exposure time: 20 hr and 44 hr Dose: 10, 50, 100 μg/mL | PC | – | | 22.0–32.0** | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (−S9) Exposure time: 20 hr and 44 hr Dose: 10, 50, 100 μg/mL | Donor 1, 20 hr | 100 | | 2.0 | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (−S9) Exposure time: 20 hr and 44 hr Dose: 10, 50, 100 μg/mL | Donor 2, 20 hr | 100 | | 12.5** | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (−S9) Exposure time: 20 hr and 44 hr Dose: 10, 50, 100 μg/mL | Donor 2. 44 hr | 100 | | 4.5* | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (+S9) Dose: Same as above | NC | – | | 1.0–1.5 | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (+S9) Dose: Same as above | PC | – | | 26–34.0** | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (+S9) Dose: Same as above | Donor 1, 20 hr | 50 | | 4.5* | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (+S9) Dose: Same as above | Donor 2, 20 hr | 100 | | 9.5** | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony trioxide NC: dimethyl sulfoxide (10 μL/mL) PC: mitomycin C (0.2 μg/mL for-S9) or cyclo-phosphamide (50 μg/mL for +S9) | In vitro exposure Metaphase analysis | Human peripheral lymphocytes with 2 hr exposure to colcemid (+S9) Dose: Same as above | Donor 2. 44 hr | 100 | | 2.0 | Precipitate formed at top dose level. | Elliott et al. (1998)
Antimony sodium tartrate | In vitro exposure Metaphase analysis | Human leucocytes Exposure time: 48 hr Concentration: 2.3 nM | 12% of cells with chromatid breaks (p < 0.05) | | | | Purity of test compound not reported; toxicity (marked reduction in mitotic index) reported at 10 nM. | Paton and Allison (1972)
Antimony trioxide VC: HPMC/poly-sorbate PC: Cyclo-phosphamide | In vivo exposure Ex vivo metaphase analysis | Sprague-Dawley rat bone marrow cells (−S9) Exposure time: Once daily for 21 consecutive days by oral gavage (except PC administered on only on day 21) Dose: 250, 500, 1,000 mg/kg | Frequency of cells with chromosomal aberration excluding gaps in male rats | | | | Body weight gain was reduced (<10%) in the top dose group of treated rats of both sexes over the 3-week dosing period. | Kirkland et al. (2007)
Antimony trioxide VC: HPMC/poly-sorbate PC: Cyclo-phosphamide | In vivo exposure Ex vivo metaphase analysis | Sprague-Dawley rat bone marrow cells (−S9) Exposure time: Once daily for 21 consecutive days by oral gavage (except PC administered on only on day 21) Dose: 250, 500, 1,000 mg/kg | Group | HIC/LEC (mg/kg) | | Mean% ± SD | Body weight gain was reduced (<10%) in the top dose group of treated rats of both sexes over the 3-week dosing period. | Kirkland et al. (2007)
Antimony trioxide VC: HPMC/poly-sorbate PC: Cyclo-phosphamide | In vivo exposure Ex vivo metaphase analysis | Sprague-Dawley rat bone marrow cells (−S9) Exposure time: Once daily for 21 consecutive days by oral gavage (except PC administered on only on day 21) Dose: 250, 500, 1,000 mg/kg | VC | 20 | | 0 ± 0 | Body weight gain was reduced (<10%) in the top dose group of treated rats of both sexes over the 3-week dosing period. | Kirkland et al. (2007)
Antimony trioxide VC: HPMC/poly-sorbate PC: Cyclo-phosphamide | In vivo exposure Ex vivo metaphase analysis | Sprague-Dawley rat bone marrow cells (−S9) Exposure time: Once daily for 21 consecutive days by oral gavage (except PC administered on only on day 21) Dose: 250, 500, 1,000 mg/kg | PC | 20 | | 13 ± 6.63*** | Body weight gain was reduced (<10%) in the top dose group of treated rats of both sexes over the 3-week dosing period. | Kirkland et al. (2007)
Antimony trioxide VC: HPMC/poly-sorbate PC: Cyclo-phosphamide | In vivo exposure Ex vivo metaphase analysis | Sprague-Dawley rat bone marrow cells (−S9) Exposure time: Once daily for 21 consecutive days by oral gavage (except PC administered on only on day 21) Dose: 250, 500, 1,000 mg/kg | Male rat | 1,000 | | 0 ± 0 | Body weight gain was reduced (<10%) in the top dose group of treated rats of both sexes over the 3-week dosing period. | Kirkland et al. (2007)
Antimony trioxide VC: HPMC/poly-sorbate PC: Cyclo-phosphamide | In vivo exposure Ex vivo metaphase analysis | Sprague-Dawley rat bone marrow cells (−S9) Exposure time: Once daily for 21 consecutive days by oral gavage (except PC administered on only on day 21) Dose: 250, 500, 1,000 mg/kg | Female rat | 1,000 | | 0 ± 0 | Body weight gain was reduced (<10%) in the top dose group of treated rats of both sexes over the 3-week dosing period. | Kirkland et al. (2007)
Antimony trioxide NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Male Swiss albino mice bone marrow cells (−S9) Exposure by daily oral gavage on days 7, 14 and 21 Dose: 400, 666.7, 1,000 mg/kg | Frequency of aberrations excluding gap | | | | Purity of test compound not reported. Test for trend significant for 7 and 14 days for analysis including and excluding gaps (not shown in this table). No increases in chromosomal aberrations were observed after single acute exposure at same doses and measured 6, 12, 18 and 24 hours); Highest dose was lethal. | Gurnani et al. (1992a)
Antimony trioxide NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Male Swiss albino mice bone marrow cells (−S9) Exposure by daily oral gavage on days 7, 14 and 21 Dose: 400, 666.7, 1,000 mg/kg | LEC (mg/kg) | Time (days) | | Mean % ± SD | | Gurnani et al. (1992a)
Antimony trioxide NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Male Swiss albino mice bone marrow cells (−S9) Exposure by daily oral gavage on days 7, 14 and 21 Dose: 400, 666.7, 1,000 mg/kg | NC | 7 | | 1.4 ± 1.140 | | Gurnani et al. (1992a)
Antimony trioxide NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Male Swiss albino mice bone marrow cells (−S9) Exposure by daily oral gavage on days 7, 14 and 21 Dose: 400, 666.7, 1,000 mg/kg | 400 | 7 | | 2.2 ± 0.447* | | Gurnani et al. (1992a)
Antimony trioxide NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Male Swiss albino mice bone marrow cells (−S9) Exposure by daily oral gavage on days 7, 14 and 21 Dose: 400, 666.7, 1,000 mg/kg | NC | 14 | | 1.6 ± 0.547 | | Gurnani et al. (1992a)
Antimony trioxide NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Male Swiss albino mice bone marrow cells (−S9) Exposure by daily oral gavage on days 7, 14 and 21 Dose: 400, 666.7, 1,000 mg/kg | 400 | 14 | | 3.2 ± 0.447* | | Gurnani et al. (1992a)
Antimony trioxide NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Male Swiss albino mice bone marrow cells (−S9) Exposure by daily oral gavage on days 7, 14 and 21 Dose: 400, 666.7, 1,000 mg/kg | NC | 21 | | 1.6 ± 0.547 | | Gurnani et al. (1992a)
Antimony trioxide NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Male Swiss albino mice bone marrow cells (−S9) Exposure by daily oral gavage on days 7, 14 and 21 Dose: 400, 666.7, 1,000 mg/kg | 400 | 21 | | 4.6 ± 0.547* | | Gurnani et al. (1992a)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | Frequency of aberrations including gap | | | | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | LEC (mg/kg) | Time (hrs) | | Mean% ± SD | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | NC | 6 | | 1.6 ± 0.547 | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | 70 | 6 | | 2.6 ± 0.547 | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | NC | 12 | | 1.0 ± 1.0 | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | 70 | 12 | | 3.0 ± 0.0 | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | NC | 18 | | 1.6 ± 0.547 | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | 70 | 18 | | 3.2 ± 0.836 | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | NC | 24 | | 1.0 ± 0.0 | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Antimony trichloride NC: distilled water | In vivo exposure Ex vivo metaphase analysis | Female Swiss albino mice bone marrow cells (−S9) Dose: 70, 140, 233.3 mg/kg Single exposure by oral gavage analyzed at 6, 12, 18 and 24 hrs | 70 | 24 | | 4.2 ± 1.095 | Source and purity of test compound not reported. Test for trend significant for 6, 12, 18, and 24 hr analysis including and excluding gaps (not shown in this table). | Gurnani et al. (1992b)
Potassium antimony tartrate Control: untreated animals | In vivo exposure Ex vivo metaphase analysis | Male rats bone marrow (−S9) Exposure via single intraperitoneal injection at each dose. Also, tested repeated exposure (daily for 5 days) at each dose. Dose: 2.0, 8.4, 14.8 mg/kg | Metaphases with aberrations excluding gap | | | | Similar findings for aberrations including gaps but statistical analysis not performed. | El Nahas et al. (1982)
Potassium antimony tartrate Control: untreated animals | In vivo exposure Ex vivo metaphase analysis | Male rats bone marrow (−S9) Exposure via single intraperitoneal injection at each dose. Also, tested repeated exposure (daily for 5 days) at each dose. Dose: 2.0, 8.4, 14.8 mg/kg | LEC (mg/kg, unless specified) | Time after treatment (hr, unless specified) | | % | Similar findings for aberrations including gaps but statistical analysis not performed. | El Nahas et al. (1982)
Potassium antimony tartrate Control: untreated animals | In vivo exposure Ex vivo metaphase analysis | Male rats bone marrow (−S9) Exposure via single intraperitoneal injection at each dose. Also, tested repeated exposure (daily for 5 days) at each dose. Dose: 2.0, 8.4, 14.8 mg/kg | NC | n/a | | 0.7 | Similar findings for aberrations including gaps but statistical analysis not performed. | El Nahas et al. (1982)
Potassium antimony tartrate Control: untreated animals | In vivo exposure Ex vivo metaphase analysis | Male rats bone marrow (−S9) Exposure via single intraperitoneal injection at each dose. Also, tested repeated exposure (daily for 5 days) at each dose. Dose: 2.0, 8.4, 14.8 mg/kg | 2.0 | 6 | | 2.0* | Similar findings for aberrations including gaps but statistical analysis not performed. | El Nahas et al. (1982)
Potassium antimony tartrate Control: untreated animals | In vivo exposure Ex vivo metaphase analysis | Male rats bone marrow (−S9) Exposure via single intraperitoneal injection at each dose. Also, tested repeated exposure (daily for 5 days) at each dose. Dose: 2.0, 8.4, 14.8 mg/kg | 2.0 | 24 | | 2.4* | Similar findings for aberrations including gaps but statistical analysis not performed. | El Nahas et al. (1982)
Potassium antimony tartrate Control: untreated animals | In vivo exposure Ex vivo metaphase analysis | Male rats bone marrow (−S9) Exposure via single intraperitoneal injection at each dose. Also, tested repeated exposure (daily for 5 days) at each dose. Dose: 2.0, 8.4, 14.8 mg/kg | 8.4 | 48 | | 5.2* | Similar findings for aberrations including gaps but statistical analysis not performed. | El Nahas et al. (1982)
Potassium antimony tartrate Control: untreated animals | In vivo exposure Ex vivo metaphase analysis | Male rats bone marrow (−S9) Exposure via single intraperitoneal injection at each dose. Also, tested repeated exposure (daily for 5 days) at each dose. Dose: 2.0, 8.4, 14.8 mg/kg | 2.0 mg/kg/day × 5 days | – | | 7.6* | Similar findings for aberrations including gaps but statistical analysis not performed. | El Nahas et al. (1982)
Micronuclei
Occupational antimony trioxide | Epidemiology study Sister chromatid exchange assay | Blood lymphocytes from textile workers exposed to low levels of antimony trioxide. 23 exposed workers: 17 high exposure (0.12 ± 11 μg/m^3^) and 6 lower exposure (0.052 ± 0.038 μg/m^3^) 23 controls | Mean micronuclei/1,000 binucleated cells did not differ between controls and two exposure groups | | | | High exposure well below OHSA permissible exposure levels and NIOSH recommended exposure levels. Exposure groups had similar ages, and smoking habits. | Cavallo et al. (2002)
Antimony trichloride NC: DMSO PC: mitomycin C (data not shown) | In vitro exposure Micronucleus test | Human peripheral lymphocytes (−S9) Doses: 0, 0.5, 2, 5, 25 μM | Induction of micronuclei by Sb(III) | | | | Co-incubation with SOD or CAT had no effect on micronucleus frequency; statistically significant in MN observed in second experiment at 5, 10 and 25 μ M. | Schaumlöffel and Gebel (1998)
Antimony trichloride NC: DMSO PC: mitomycin C (data not shown) | In vitro exposure Micronucleus test | Human peripheral lymphocytes (−S9) Doses: 0, 0.5, 2, 5, 25 μM | LEC (μM) | Time (hrs) | | MN/1000 BN, mean ± SD | Co-incubation with SOD or CAT had no effect on micronucleus frequency; statistically significant in MN observed in second experiment at 5, 10 and 25 μ M. | Schaumlöffel and Gebel (1998)
Antimony trichloride NC: DMSO PC: mitomycin C (data not shown) | In vitro exposure Micronucleus test | Human peripheral lymphocytes (−S9) Doses: 0, 0.5, 2, 5, 25 μM | 0 | 20 | | 10 ± 1.4 | Co-incubation with SOD or CAT had no effect on micronucleus frequency; statistically significant in MN observed in second experiment at 5, 10 and 25 μ M. | Schaumlöffel and Gebel (1998)
Antimony trichloride NC: DMSO PC: mitomycin C (data not shown) | In vitro exposure Micronucleus test | Human peripheral lymphocytes (−S9) Doses: 0, 0.5, 2, 5, 25 μM | 5 | 20 | | 30.5 ± 2.1 | Co-incubation with SOD or CAT had no effect on micronucleus frequency; statistically significant in MN observed in second experiment at 5, 10 and 25 μ M. | Schaumlöffel and Gebel (1998)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Male mice peripheral blood erythrocytes exposed via inhalation for 12 months Dose: 0, 3, 10, 30 mg/m^3^ | No significant increase in micronucleated PCEs/1,000 PCEs in male mice | | | | Twenty thousand CD71+ reticulocytes (PCE) were scored per animal for the presence of micronuclei and 1 × 10^6^ erythrocytes (NCE) were counted for micronuclei. Williams’s and Dunn’s tests were used for pairwise significance, and Jonckheere’s test and linear regression used for trend significance. MN frequency in NCEs but not PCEs significant by trend test (p < 0.001) in both sexes. | NTP (2017a)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Male mice peripheral blood erythrocytes exposed via inhalation for 12 months Dose: 0, 3, 10, 30 mg/m^3^ | Micronucleated NCEs/1,000 NCEs | | | | | NTP (2017a)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Male mice peripheral blood erythrocytes exposed via inhalation for 12 months Dose: 0, 3, 10, 30 mg/m^3^ | LEC (mg/m^3^) | Time (mo.) | | Mean ± SE | | NTP (2017a)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Male mice peripheral blood erythrocytes exposed via inhalation for 12 months Dose: 0, 3, 10, 30 mg/m^3^ | 30 | 12 | | 1.93 ± 0.10*** | | NTP (2017a)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Female mice peripheral blood erythrocytes exposed via inhalation for 12 months Dose: 0, 3, 10, 30 mg/m^3^ | No significant increase in micronucleated PCEs/1,000 PCEs in female mice | | | | | NTP (2017a)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Female mice peripheral blood erythrocytes exposed via inhalation for 12 months Dose: 0, 3, 10, 30 mg/m^3^ | Micronucleated NCEs/1,000 NCEs | | | | | NTP (2017a)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Female mice peripheral blood erythrocytes exposed via inhalation for 12 months Dose: 0, 3, 10, 30 mg/m^3^ | LEC (mg/m^3^) | Time (mo.) | | Mean ± SE | | NTP (2017a)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Female mice peripheral blood erythrocytes exposed via inhalation for 12 months Dose: 0, 3, 10, 30 mg/m^3^ | 30 | 12 | | 1.38 ± 0.09*** | | NTP (2017a)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Male rat peripheral blood erythrocytes exposed via inhalation for 12 months | No significant increase in micronucleated PCEs/1,000 PCEs or micronucleated NCEs/1,000 NCEs in male rats. | | | | Twenty thousand CD71+ reticulocytes (PCE) were scored per animal for the presence of micronuclei and 1 × 10^6^ erythrocytes (NCE) were counted for micronuclei. Williams’s and Dunn’s tests were used for pairwise significance, and Jonckheere’s test and linear regression used for trend significance. No significant changes were observed in MN frequency in rats of either sex. | NTP (2017a)
Antimony trioxide NC: air | In vivo exposure Ex vivo micronucleus test | Female rat peripheral blood erythrocytes exposed via inhalation for 12 months | No significant increase in micronucleated PCEs/1,000 PCEs or micronucleated NCEs/1,000 NCEs in female rats. | | | | | NTP (2017a)
Antimony trichloride | In vitro exposure Micronucleus test | Human fibroblast cells (−S9) Human bronchial epithelial cells (BES-6) (−S9) Chinese hamster ovary cells (CHO-K1) (−S9) Exposure time: 4 hr, Dose: 50–400 μM | Positive findings for all cell types at all doses | | | | LD_50_ = 40 μM in fibroblast cells LD_50_ = 80 μM in BES-6 cells LD_50_ = 180 μM in CHO-K1 cells | Huang et al. (1998)
Antimony trioxide VC: DMSO PC: Cyclo-phosphamide (20 mg/kg) | In vivo exposure Micronucleus test | Mouse bone marrow (−S9) male and females Single dose study Exposure time: 24 and 48 hr Dose: 5,000 mg/kg by oral gavage Repeated dose study: Exposure time: 8, 15 and 22 days Dose: 400, 667, or 1,000 mg/kg by oral gavage | No increases in mean incidence of MPE/1,000 PE in the single dose study (males and females) or in the repeated dose study (sex not identified). | | | | Significantly decreased frequency of polychromatic erythrocytes observed in females at 24 hr in the single dose experiment. | Elliott et al. (1998)
Antimony trioxide VC: HPMC/poly-sorbate PC: Cyclo-phosphamide (20 mg/kg) | In vivo exposure Micronucleus test | Sprague-Dawley male and female rat bone marrow cells (−S9) Exposure time: 21 days (except for PCs) by oral gavage Dose: 250, 500, 1,000 mg/kg | No increase in the frequency of micronucleated PCE in male and female rats | | | | – | Kirkland et al. (2007)
Antimony trioxide VC: DMSO (25 μL) PC: Mitomycin C (0.5 μM) | In vitro Micronucleus test with cytokinesis block | Chinese hamster V79 cells Exposure time: 24 hr Dose: 2–50 μM | Mean number of micronuclei | | | | Study measured both antimony uptake in cells and cytotoxicity (50% neutral red uptake was found with SbCl_3_ at 83 μM). | Gebel et al. (1998)
Antimony trioxide VC: DMSO (25 μL) PC: Mitomycin C (0.5 μM) | In vitro Micronucleus test with cytokinesis block | Chinese hamster V79 cells Exposure time: 24 hr Dose: 2–50 μM | Group | LEC (μM) | | Mean | Study measured both antimony uptake in cells and cytotoxicity (50% neutral red uptake was found with SbCl_3_ at 83 μM). | Gebel et al. (1998)
Antimony trioxide VC: DMSO (25 μL) PC: Mitomycin C (0.5 μM) | In vitro Micronucleus test with cytokinesis block | Chinese hamster V79 cells Exposure time: 24 hr Dose: 2–50 μM | VC | – | | 9.5 | Study measured both antimony uptake in cells and cytotoxicity (50% neutral red uptake was found with SbCl_3_ at 83 μM). | Gebel et al. (1998)
Antimony trioxide VC: DMSO (25 μL) PC: Mitomycin C (0.5 μM) | In vitro Micronucleus test with cytokinesis block | Chinese hamster V79 cells Exposure time: 24 hr Dose: 2–50 μM | PC | – | | 45.5 | Study measured both antimony uptake in cells and cytotoxicity (50% neutral red uptake was found with SbCl_3_ at 83 μM). | Gebel et al. (1998)
Antimony trioxide VC: DMSO (25 μL) PC: Mitomycin C (0.5 μM) | In vitro Micronucleus test with cytokinesis block | Chinese hamster V79 cells Exposure time: 24 hr Dose: 2–50 μM | Antimony trioxide | 25 | | 17.5 | Study measured both antimony uptake in cells and cytotoxicity (50% neutral red uptake was found with SbCl_3_ at 83 μM). | Gebel et al. (1998)
Sister chromatid exchange
Occupational antimony trioxide | Epidemiology study Sister chromatid exchange assay | Peripheral blood lymphocytes from textile workers exposed to low levels of antimony trioxide 23 exposed workers: 17 high exposure (0.12 ± 11 μg/m^3^) and 6 lower exposure (0.052 ± 0.038 μg/m^3^) 23 controls | Mean SCE did not differ between controls and two exposure groups | | | | High exposure well below OHSA permissible exposure levels and NIOSH recommended exposure levels. Exposure groups had similar ages, and smoking habits. | Cavallo et al. (2002)
Antimony trioxide (dissolved in distilled water) NC: DMSO | In vitro exposure Sister chromatid exchange assay | Human peripheral blood lymphocytes from healthy non-smokers aged 25–35 years (−S9) Exposure time: 24 hrs | SCE/cell | | | | NC was DMSO, and it is unclear whether the 0 μM result was from distilled water or DMSO. No PC was stated in the study. Results are from 60 metaphase cells scored on two slides. | Gebel et al. (1997)
Antimony trioxide (dissolved in distilled water) NC: DMSO | In vitro exposure Sister chromatid exchange assay | Human peripheral blood lymphocytes from healthy non-smokers aged 25–35 years (−S9) Exposure time: 24 hrs | LEC (μM) | | Mean ± SD | | NC was DMSO, and it is unclear whether the 0 μM result was from distilled water or DMSO. No PC was stated in the study. Results are from 60 metaphase cells scored on two slides. | Gebel et al. (1997)
Antimony trioxide (dissolved in distilled water) NC: DMSO | In vitro exposure Sister chromatid exchange assay | Human peripheral blood lymphocytes from healthy non-smokers aged 25–35 years (−S9) Exposure time: 24 hrs | 0 | | 8.6 ± 3.4 | | NC was DMSO, and it is unclear whether the 0 μM result was from distilled water or DMSO. No PC was stated in the study. Results are from 60 metaphase cells scored on two slides. | Gebel et al. (1997)
Antimony trioxide (dissolved in distilled water) NC: DMSO | In vitro exposure Sister chromatid exchange assay | Human peripheral blood lymphocytes from healthy non-smokers aged 25–35 years (−S9) Exposure time: 24 hrs | 0.5 | | 11.5 ± 4.4* | | NC was DMSO, and it is unclear whether the 0 μM result was from distilled water or DMSO. No PC was stated in the study. Results are from 60 metaphase cells scored on two slides. | Gebel et al. (1997)
Antimony trichloride (dissolved in DMSO) NC: DMSO | In vitro exposure Sister chromatid exchange assay | Human peripheral blood lymphocytes from healthy non-smokers aged 25–35 years (−S9) Exposure time: 24 hr | SCE/cell | | | | No PC was stated in the study. Results are from 60 metaphases scored on two slides.NC was DMSO, and it is unclear whether the 0 μM result was from distilled water or DMSO. | Gebel et al. (1997)
Antimony trichloride (dissolved in DMSO) NC: DMSO | In vitro exposure Sister chromatid exchange assay | Human peripheral blood lymphocytes from healthy non-smokers aged 25–35 years (−S9) Exposure time: 24 hr | LEC (μM) | | Mean ± SD | | No PC was stated in the study. Results are from 60 metaphases scored on two slides.NC was DMSO, and it is unclear whether the 0 μM result was from distilled water or DMSO. | Gebel et al. (1997)
Antimony trichloride (dissolved in DMSO) NC: DMSO | In vitro exposure Sister chromatid exchange assay | Human peripheral blood lymphocytes from healthy non-smokers aged 25–35 years (−S9) Exposure time: 24 hr | 0 | | 8.8 ± 4.0 | | No PC was stated in the study. Results are from 60 metaphases scored on two slides.NC was DMSO, and it is unclear whether the 0 μM result was from distilled water or DMSO. | Gebel et al. (1997)
Antimony trichloride (dissolved in DMSO) NC: DMSO | In vitro exposure Sister chromatid exchange assay | Human peripheral blood lymphocytes from healthy non-smokers aged 25–35 years (−S9) Exposure time: 24 hr | 1 | | 13.8 ± 5.5** | | No PC was stated in the study. Results are from 60 metaphases scored on two slides.NC was DMSO, and it is unclear whether the 0 μM result was from distilled water or DMSO. | Gebel et al. (1997)
Antimony trioxide NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 0.09–0.34 μg/mL | Frequency of sister chromatid exchanges/metaphase | | | | Sb_2_O_5_ was negative in the SCE assay; similar results in experiment 1, although LEC was 0.17 μg/mL. | Kuroda et al. (1991)
Antimony trioxide NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 0.09–0.34 μg/mL | LEC (μg/mL) | Time (hrs) | | Mean ± SD | Sb_2_O_5_ was negative in the SCE assay; similar results in experiment 1, although LEC was 0.17 μg/mL. | Kuroda et al. (1991)
Antimony trioxide NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 0.09–0.34 μg/mL | NC | 28 | | 6.3 ± 2.5 | Sb_2_O_5_ was negative in the SCE assay; similar results in experiment 1, although LEC was 0.17 μg/mL. | Kuroda et al. (1991)
Antimony trioxide NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 0.09–0.34 μg/mL | PC | 28 | | 56.0 ± 9.3** | Sb_2_O_5_ was negative in the SCE assay; similar results in experiment 1, although LEC was 0.17 μg/mL. | Kuroda et al. (1991)
Antimony trioxide NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 0.09–0.34 μg/mL | 0.09 | 28 | | 10.6 ± 3.7** | Sb_2_O_5_ was negative in the SCE assay; similar results in experiment 1, although LEC was 0.17 μg/mL. | Kuroda et al. (1991)
Antimony trichloride NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 1.3–20 μg/mL | Frequency of sister chromatid exchanges/metaphase | | | | SbCl_5_ was negative in the SCE assay. Toxic at 20 μg/mL; similar results in experiment 2, although LEC was 5 μg/mL. | Kuroda et al. (1991)
Antimony trichloride NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 1.3–20 μg/mL | Conc. (μg/mL) | Time (hrs) | | Mean ± SD | SbCl_5_ was negative in the SCE assay. Toxic at 20 μg/mL; similar results in experiment 2, although LEC was 5 μg/mL. | Kuroda et al. (1991)
Antimony trichloride NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 1.3–20 μg/mL | NC | 28 | | 4.5 ± 2.2 | SbCl_5_ was negative in the SCE assay. Toxic at 20 μg/mL; similar results in experiment 2, although LEC was 5 μg/mL. | Kuroda et al. (1991)
Antimony trichloride NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 1.3–20 μg/mL | PC | 28 | | 46.8 ± 8.6** | SbCl_5_ was negative in the SCE assay. Toxic at 20 μg/mL; similar results in experiment 2, although LEC was 5 μg/mL. | Kuroda et al. (1991)
Antimony trichloride NC: Water (100 μL) PC: Mitomycin C (0.01 μg/mL) | In vitro exposure Sister chromatid exchange assay | Chinese hamster V79 cells Exposure time: 28 hr Dose: 1.3–20 μg/mL | 2.5 | 28 | | 7.5 ± 4.3* | SbCl_5_ was negative in the SCE assay. Toxic at 20 μg/mL; similar results in experiment 2, although LEC was 5 μg/mL. | Kuroda et al. (1991)

* p < 0.05, **p < 0.01, ***p < 0.001.

Studies are listed hierarchically according to the following criteria (1): Assay, in the order of assays for chromosomal aberrations, micronucleus, and sister chromatid exchange. (2): Target system, in the order of studies in human cells, animal studies, in vitro studies, biochemical studies. (3) Compound, in the order of antimony trioxide (bold), antimony trichloride, other antimony(III) compounds.

b.w. = body weight; FISH = fluorescence in situ hybridization; HIC = highest ineffective concentration; hr = hour(s); LEC = lowest effective concentration; mo = months; NC = negative control; NR = not reported; PC = positive control; VC = vehicle control.

^a^ Provided are the form of the test compound, study details including the testing system and exposure duration, assay endpoint results for test compounds and positive and negative controls, comments provided by reviewers, and reference.

^b^ Compounds containing pentavalent antimony are not included. For instance, trimethylantimony dichloride in Dopp et al. (2006) (no increase of MN formation, chromosome aberration, or sister chromatid exchange in the Chinese hamster ovary cells after exposure to at up to 1 mM. When the cells underwent electroporation to double the intake of trimethylantimony dichloride, the formation of MN was increased.) and KSbO3 in Migliore et al. (1999) (nonsignificant increase of centromere-negative MN) were not included in the table.

## E.4 Studies Related to Cell Proliferation

Table E-5 Mutations in the Lung of Mice and Rats after Two-year Inhalation Exposure to Antimony Trioxide (NTP 2017a)

Genotoxicity Endpoint | Testing System | Mutation Frequency | | Comments | Reference
| | Concentration (mg/m^3^) | # with mutation/# tissues assayed
Egfr mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 0 (nontumor lung) | 0/10 | – | NTP (2017a)
Egfr mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 0 (tumor lung) | 0/9* | – | NTP (2017a)
Egfr mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 3 (tumor lung) | 11/28** | – | NTP (2017a)
Egfr mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 10 (tumor lung) | 11/26** | – | NTP (2017a)
Egfr mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 30 (tumor lung) | 15/26*** | – | NTP (2017a)
Egfr mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 0 (nontumor lung) | 0/11 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Egfr mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 0 (tumor lung) | 0/4 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Egfr mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 3 (tumor lung) | 3/5 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Egfr mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 10 (tumor lung) | 6/11 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Egfr mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 30 (tumor lung) | 4/10 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 0 (nontumor lung) | 0/11 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 0 (tumor lung) | 0/4 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 3 (tumor lung) | 0/5 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 10 (tumor lung) | 1/11 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed Wistar Han rats. Both nontumor lung and spontaneous tumors from control mice. | 30 (tumor lung) | 0/10 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 0 (nontumor lung) | 0/10 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 0 (tumor lung) | 3/9 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 3 (tumor lung) | 9/28 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 10 (tumor lung) | 15/26 | Increase was [underlined: not] statistically significant. | NTP (2017a)
Kras mutations | Lung tumors from exposed B6C3F1/N mice. Both nontumor lung and spontaneous tumors from control mice. | 30 (tumor lung) | 10/26 | Increase was [underlined: not] statistically significant. | NTP (2017a)

* Significant exposure-concentration trend (p ≤ 0.01) by the Cochran-Armitage trend test.

** Significantly different (p ≤ 0.05) from the chamber control group by the one-sided Fisher’s exact test.

*** p ≤ 0.005.

## E.5 Transcriptomic of Antimony(III) Potassium Tartrate Trihydrate in HepG2 Cells

One DNA microarray study (Kawata et al. 2007) of in vitro effects of an antimony(III) compound on a human cell line was found in the National Center for Biotechnology Information Gene Expression Omnibus (NCBI GEO) database (NCBI 2017). HepG2 (human liver carcinoma) cells were exposed to bis[(+)-tartato]diantimonate(III) dipotassium trihydrate (i.e., antimony(III) potassium tartrate trihydrate, equivalent to one molecule of antimony(III) potassium tartrate plus three water molecules) at a concentration of 200 μM for 6 hours, and the gene expression changes seen in a Human Genome Focus array (Affymetrix) were compared with changes following exposure to five other substances, including arsenic(III) oxide at 20 μM and nickel(III) chloride hexahydrate at 6.5 nM. The gene expression profile after antimony(III) potassium tartrate trihydrate exposure was most similar to that after nickel(III) chloride hexahydrate exposure.

The microarray data were downloaded from the NCBI GEO database and analyzed in Ingenuity Pathway Analysis (Qiagen) by the NTP ORoC, using the filter of minimal 2-fold change. Of the top ten canonical pathways affected (Table E-6), seven were related to immune reactions (pathways 1, 2, 4, 5, 7, 8, and 9). These findings are consistent with the former use of antimony(III) potassium tartrate as an antiparasitic agent for leishmaniasis. The other three pathways were eicosanoid signaling, bladder cancer signaling, and detoxification of oxidized guanosine triphosphate (GTP) and deoxyguanosine triphosphate (dGTP). Although antimony is not known to cause urinary bladder cancer, the chemically similar arsenic increases the incidence of transitional-cell carcinoma of the urinary bladder in humans. An effect on the oxidized GTP and dGTP detoxification pathway is consistent with the observation that various antimony compounds increase oxidative stress (as discussed in Section 6.2).

In the upstream analysis, the top three affected regulators were vascular endothelial growth factor (VEGF), colony-stimulating factor 2 (CSF2) (a cytokine), and the triggering receptor expressed on myeloid cells 1 (TREM1), which stimulates neutrophil- and monocyte-mediated inflammatory responses (Appendix E.5, Table E-6). In a 2015 study, antimony(III) potassium tartrate inhibited the VEGF-induced formation of capillary-like structures in endothelial cells (Wang et al. 2015). In other words, antimony(III) potassium tartrate showed anti-tumor effects via anti-angiogenesis in cultured cells. Both CSF2 and TREM1 stimulate immune or inflammatory responses. These top three affected regulators are predominantly involved in skin disease and cancer. Some anti-cancer effects, such as increased differentiation of cells, were also enriched in the gene expression. To identify key factors contributing to potential carcinogenic effects, further analysis is needed. It is also possible that 6-hour exposure leads to mostly acute responses, which may differ from the long-term effects.

Table E-6 Top 10 Upstream Regulators for Antimony

| Upstream Regulator | Expr Fold Change | Molecule Type | Predicted Activation State | Activation z-score | Flags | P Value of Overlap | Target Molecules in Dataset | Mechanistic Network
1 | Vegf | – | group | Activated | 9.487 | bias | 1.88E-09 | ANGPT2,ANGPTL4,AQP4,ATF3,AURKA,AURKB,BCL2A1,BIRC5,BNC1,BTN1A1,CA2,CALB1,CALCRL,CCL7,CCNF,CD3EAP,CDC14A,CDC20,CDC25A,CDC25B,CDC25C,CDC45,CDH5,CDK1,CDKN2C,CDKN3,CELSR1,CHI3L1,CHIA,CHRNB2,CHST7,CKS1B,CLCF1,CNN1,CNTFR,CPA3,CRLF1,CRYAB,CSF2,CXCL1,CXCL8,CXCR2,CXCR4,CYR61,DBF4,DPF3,DRD3,DTYMK,DUSP4,DUSP5,EDN1,EGR1,EGR3,EMCN,EMP2,ESM1,FABP4,FAIM2,FANCG,FGF16,FGF2,FLNA,FOSB,FOSL1,GATA1,GEM,GH1,GPR4,GPRC5B,HBE1,HBEGF,HDC,HMOX1,HOXB8,HPSE,HTR7,IL18,IL1A,IL3RA,IL4,ITGB3BP,JAM2,JUN,KIF15,KIF22,KIF2C,KITLG,LEF1,LPAR1,LRAT,LYVE1,MCM2,MCM5,MID1,MKI67,MMP10,MMP14,MT1G,MYCN,NDC80,NEK2,NFATC1,NGB,NR4A2,NR4A3,NRCAM,NRG1,PLK1,PLXNA2,PMAIP1,PRC1,PRKCB,PSMC3IP,PTH,RGS2,RGS20,SOCS2,SOCS3,ST8SIA4,STK10,TAAR5,TACR1,TACSTD2,TBXA2R,THBD,TNC,TNFRSF9,TNFSF15,TPX2,TRAF5,TRAIP,TRPC4,TTK,UBE2C,XCR1 | –
2 | CSF2 | 8.025 | cytokine | Activated | 8.308 | bias | 1.85E-08 | ADA,ADAM8,ADGRE5,ANXA1,AURKA,BCL2A1,BIRC5,C5AR1,CCL4,CCNF,CCR1,CCR5,CCR7,CD1C,CD209,CD28,CD33,CD40LG,CD69,CD8A,CDC20,CDK1,CDKN1A,CDKN2B,CDKN2C,CENPE,CHAF1A,CHAF1B,CKS1B,CLCF1,COL8A1,CSF1,CSF2,CTLA4,CXCL1,CXCL2,CXCL8,CXCR4,CYBB,EDN1,EGR1,EGR2,EGR3,EPOR,EXO1,FANCA,FCGR2B,FOLR2,FOS,FOSL1,FPR2,GATA1,GCLM,GDF15,HBEGF,HDC,HLA-DQB1, HRH4,HRK,HSPH1,IER3,IFNG,IGF1,IL1A,IL1RN,IL24,IL3RA,IL4,ITGA4,ITGAM,LEP,MCM5,MKI67,MMP1,MMP14,MRC1,NEK2,NFATC1,NFE2,NFKBIA,NR4A2,NUSAP1,OSM,PDE1B,PIM1,PLK1,POLD1,POLE,PPP1R15A,PRC1,PTGER2,RARA,RECQL4,RELB,RRM2,SERPINB9,SLC1A5,SOCS2,SOCS3,SPAG5,SPI1,STMN1,THBS1,TLR2,TLR4,TNFAIP3,TNFRSF1B,TNFRSF9,TNFSF14,TNFSF15,TNFSF8,TPM4,TPX2,UBE2C, ZFP36 | 352 (5)
3 | TREM1 | 1.62 | transmembrane receptor | Activated | 4.945 | bias | 0.000000203 | ATF3,CASP5,CCL7,CCR7,CCRL2,CDK1,CDKN2B,CEBPB,CKS2,CSF1,CSF2,CXCL1,CXCL2,CXCL3,CXCL5,CXCL8,CXCR4,DCSTAMP,DEFB4A/DEFB4B,DUSP4,EDN1,EGR1,EGR2,EGR3,FOSL1,GADD45B,GCLM,GEM,GIPR,GLA,HAS1,HBEGF,IFNG,IL17A,IL36RN,IL4,LPL,MAD1L1,MAFF,MMP1,MMP10,MMP19,NFKBIA,NOD2,NR4A2,OSGIN1,RGS1,RRAD,SLC1A3,SNAPC1,TCEAL9,THBD,THBS1,TLR2,TLR4,TNFSF14,TNFSF15,WNT5A | –
4 | GATA2 | 2.854 | transcription regulator | – | 1.922 | – | 0.000000237 | ADGRE5,ANGPT2,ANGPTL4,ARPP21,C9,CCL21,CCR8,CD177,CD34,CD36,CD69,CD96,CDH5,CDK6,CDKN1A,CEL,CELSR3,CHGA,CHI3L1,CLDN18,CMA1,CPA1,CPA3,CST7,CYBB,CYP2F1,CYP4F11,DDX4,DLK1,E2F2,EDN1,ELANE,EMCN,EPHA3,FABP4,FCN1,GABRP,GATA1,GATA2,GP5,GP9,GPR65,GUCA2A,HBQ1,HDC,HOXA10,HSD17B1,ICAM2,IKZF1,IL3RA,IL4,IL4R,ITGAM,KLF2,KLK3,LYL1,MAFB,MEP1A,MMRN1,MPIG6B,NFE2,PAX3,PDE9A,PLK2,PRG3,RAG1,REG1A,S100A5,S100A9,S100G,SERPINB10,SLC4A1,SLC9A5,SOX18,SPI1,SSTR2,TAC3,TACSTD2,TAL1,THBS1,TUBA8,UBASH3A | –
5 | calcitriol | – | chemical drug | – | 0.412 | – | 0.000000494 | ADAM19,ALPI,ANGPT2,ANKRD2,ATP5D,BIRC5,CA2,CALB1,CALCB,CASR,CCNA1,CCR8,CDC20,CDC45,CDK1,CDK5R1,CDKN1A,CEBPB,CELSR3,CHAF1A,CHAF1B,CHGA,CKM,COL4A1,CSF1,CSF2,CXCL2,CXCL3,CXCL8,CYP24A1,CYP2C9,CYP3A4,CYP46A1,CYR61,DCSTAMP,DEFB4A/DEFB4B,DUSP1,DUSP10,EDN1,EGR1,ETFB,EXO1,FABP4,FAM107A,FCER2,FOS,GADD45A,GADD45G,GEM,HBEGF,HSPB7,IER3,IFITM1,IFNG,IGF1,IGFBP5,IL10RA,IL17A,IL18,IL1A,IL1RN,IL4,INCENP,INS,ITGA4,ITGAM,ITGB7,JUN,KIF20A,KIF22,KL,KLK13,KLK5,LEP,LIG1,LPAR1,LPL,LTBP1,MAOA,MCM2,MCM5,MMP1,MRC1,MYH8,NEK2,NFATC1,NKX2-1,NME4,NPHS1, NTHL1,NUPR1,NUSAP1,PDE9A,POLE,POU1F1,PRC1,PRKCB,PRKCD,PTGER2,PTGFR,PTH,RAB38,RAD51AP1,RARRES1,RBPMS,REL,RRM2,RUNX1T1,S100A9,S100G,SERPINB7,SERPINB9,SLC2A4,SLC7A7,SNPH,SOCS3,SPAG5,STMN1,SUV39H1,TACC3,TERT,THBD,THBS1,THRA,TK1,TLR2,TLR4,TNFAIP3,TPX2,TSPO,WNT11 | 140 (2)
6 | ID2 | 1.706 | transcription regulator | – | −1.136 | – | 0.000000514 | AICDA,ASCL2,BATF,CCR10,CCR7,CCR8,CD40LG,CDC25B,CDK1,CDKN1A,CDKN2C,CEBPB,CSF1,CXCR4,CXCR5,DUSP1,DUSP10,DUSP4,E2F2,EGR2,EGR4,FLT3LG,FOXO3,FSHB,GADD45B,GADD45G,IFNG,IL10RA,IL4,IL4R,IL9R,IRF8,KLF6,LTA,MAP3K14,MPZ,NFAT5,NFATC1,NR4A3,PDCD1,PTPN13,PTPN14,PTPN22,RAPGEF4,REL,RPS6KA2,SELL,SEMA3F,SH2D1A,SOCS3,SOX4,SOX5,TNFRSF25,TNFSF14,TNFSF8,TRAF1,TRAF5 | –
7 | phorbol myristate acetate | – | chemical drug | Activated | 7.684 | bias | 0.000000604 | ADAM28,ADAM8,ADM,ADRB3,AGER,ALOX12,ANGPT2,ANGPTL4,ANXA1,AQP4,ATP2A3,AURKA,AURKB,BCL2A1,BDNF,BIRC5,BLM,BTG2,C5AR1,CA2,CA8,CAV1,CCL1,CCL4,CCNA1,CCR7,CD209,CD28,CD36,CD40LG,CD69,CDK1,CDK5R1,CDK5R2,CDKN1A,CDKN2B,CGA,CHGA,CKM,CLCF1,CRH,CRHR1,CSF1,CSF2,CTLA4,CXCL13,CXCL2,CXCL3,CXCL8,CXCR2,CXCR4,CYBB,CYP24A1,CYP2A6 (includes others),CYR61,DEFB4A/DEFB4B,DSG1,DUSP1,DUSP2,DUSP5,E2F1,E2F3,EGR1,EGR2,EGR3,EGR4,EIF4EBP1,ELANE,EN1,EP300,EPOR,ERBB4,FGF2,FGF7,FOS,FOSB,FOSL1,FSHB,FUT9,GABRP,GAP43,GATA1,GATA2,GDF15,GEM,GML,GNRH1,GRIN2A,H1FX,HAS1,HBEGF,HDC,HMGA1,HPSE,HSD11B1,HSD17B1,HSD3B1,HTR2A,HTR7,IFNG,IGF1,IGFBP2,IGFBP5,IL12RB1,IL17A,IL18,IL1A,IL1RN,IL20RA,IL24,IL4,ITGAM,ITM2A,JUN,JUNB,JUND,KCNJ10,KIF2C,KLF2,KLF6,KLK3,KRT35,LAMB3,LOR,LPL,LTA,LYVE1,MAD1L1,MMP1,MMP11,MMP12,MMP14,MMP19,MMP7,MPZ,MRC1,MSR1,MST1R,MT2A,MUC4,MYH7,MYOZ2,NCR1,NFAT5,NFATC1,NFKBIA,NFKBIE,NKX2-1,NOCT,NR4A2,NTS,OLR1,OSM,OSR2,PAK2,PDCD1,PDE1C,PDPN,PIM1,PLIN3,PODXL2,PON1,POU1F1,PPP1R15A,PRKCB,PRKCD,PRKD1,PTGER2,PTGES,PTGFR,PTPRE,PTPRN,PTPRO,RAE1,RARA,RARB,RASGRP1,RECQL4,REL,RELB,RGS1,RGS2,RUVBL2,S100A9,SELL,SELPLG,SERPINB10,SERPINB7,SERPINB9,SLC22A1,SLC6A2,SLC6A7,SLC7A11,SNAI1,SNAP25,SOCS3,SP4,SPHK1,SRC,SRD5A2,SSTR2,STATH,TACR1,TBXAS1,TEAD4,TERT,TH,THBS1,TIE1,TK1,TLR2,TLR4,TLR6,TMOD2,TNFAIP3,TNFRSF1B,TNFSF14,TRAF1,TRPC6,ULBP2,USF2,VIP,WT1,XCR1,ZFP36 | 276 (3)
8 | HDAC1 | 0.743 | transcription regulator | – | −0.945 | – | 0.000000942 | ADIPOQ,AMPD3,ANGPT2,ASCL2,ATF3,BDNF,CCNA1,CCNB2,CCR8,CD27,CD34,CDC25A,CDC25C,CDK1,CDKN1A,COL1A2,COL9A1,CXCL8,E2F2,EGR1,EHMT2,FABP4,FAM107A,FOS,H2AFX,HBE1,HBG2,IFNB1,IL17A,IL24,IL4,INA,ITGB4,KLK3,LIG1,MAD1L1,MCM5,MPZ,MT1G,MUC4,MYH7,NEFH,NFATC1,NFKBIA,NKX2-5, PAX3, PLK1, PMAIP1, POLL, PPP2R2B,PRIM2,PTH,RAD54L,RAG1,RECQL4,RELB,RGS10,RRM2,RUNX2,S100A9,SATB1,SNAI1,SOX10,TAGLN,TAL1,TBX1,TBX2,TERT,TUBB3,TYMS | 414 (12)
9 | PTGER2 | 2.853 | g-protein coupled receptor | Activated | 5.127 | bias | 0.00000162 | AURKA,CCNB2,CCR7,CDKN3,CENPE,CFP,CKS2,CXCL8,CXCR2,CXCR4,EGR1,FPR1,H2AFX,HAMP,HDC,HIST1H2AB,IFNG,IL17A,IL1A,KIF15,KIF20A,KIF22,KIF2C,KLRD1,MKI67,NEK2,NUSAP1,PIM1,PLK1,PRC1,PTGER3,PTGES,SPAG5,THBS1,TPX2,TROAP,TTK | –
10 | TNF | 1.621 | cytokine | Activated | 8.752 | bias | 0.00000184 | ACTA1,ADAM8,ADAMTS5,ADIPOQ,ADM,ADRB1,ADRB3,AEBP1,AGER,AICDA,AMPD3,ANGPT2,ANGPTL4,ANXA1,ARHGDIB,ATF3,AURKC,BCL2A1,BDKRB1,BDKRB2,BDNF,BIK,BIRC5,BTG2,BTG3,C5AR1,CA2,CABP1,CAV1,CCK,CCL1,CCL22,CCL4,CCL7,CCR1,CCR5,CCR7,CCR8,CD1C,CD209,CD247,CD28,CD36,CD3E,CD40LG,CD5,CD69,CD82,CDC25C,CDH13,CDH5,CDK5R1,CDKN1A,CDKN2C,CDX1,CEBPB,CEBPG,CHI3L1,CHRNA4,CHRNB2,CHRNE,CHRNG,CHST4,CHST7,CIB2,CKM,CLCF1,CLDN7,CNN1,COL15A1,COL16A1,COL1A2,COLQ,COTL1,CPA3,CRH,CRHR1,CRLF1,CRYAB,CSF1,CSF2,CSN2,CST7,CTLA4,CTSF,CX3CR1,CXCL1,CXCL13,CXCL2,CXCL3,CXCL5,CXCL8,CXCR2,CXCR4,CXCR5,CYBB,CYP26B1,CYP2C8,CYR61,CYTH3,DCSTAMP,DEFB4A/DEFB4B,DPF3,DUSP1,DUSP10,DUSP2,DUSP4,DUSP5,DVL1,E2F1,EDN1,EGR1,EGR2,EGR3,ELF3,EMCN,EMP2,ENG,ENPP3,EREG,ESM1,FABP4,FAT2,FCAR,FCER2,FCGR2B,FGF2,FGF5,FOS,FOSB,FOSL1,FOXF1,FOXF2,FPR1,FPR2,FSCN1,G0S2,GABRA1,GADD45A,GADD45B,GADD45G,GATA2,GCLM,GDF15,GEM,GNA15,GNL1,GPR176,GPRC5B,GRIA1,HAS1,HBEGF,HDC,HIVEP1,HLA-F, HMOX1,HOXB8,HRK,HSD11B1, HSPA1A/HSPA1B,HSPG2,ICAM2,IER2,IER3,IFI27,IFITM1,IFNA1/IFNA13,IFNB1,IFNG,IGF1,IGFBP2,IGFBP5,IL10RA,IL17A,IL18,IL18R1,IL1A,IL1RN,IL24,IL3,IL36RN,IL3RA,IL4,IL4R,INS,IRF8,ITGA4,ITGAM,ITGB7,JUN,JUNB,JUND,KIF20A,KITLG,KL,KLF10,KLF2,KLF6,KLK3,LAMA4,LAMB3,LBP,LEP,LPL,LTB4R2,LYVE1,MADCAM1,MAFF,MAP3K14,MC1R,MCF2,MECOM,MFHAS1,MGMT,MMP1,MMP10,MMP12,MMP14,MMP28,MMP7,MSR1,MST1R,MSTN,MT2A,MUC1,MUC4,MYH7,NCAN,NCF2,NEFH,NFATC1,NFKBIA,NFKBIE,NKX21, NKX6-1, NOCT,NOD2,NPHS1,NPPB,NR4A2,NR4A3,NR6A1, OAS2,OLR1,OSM,OTUD7B,P2RY6,PAK2,PAX6,PDCD1,PDE2A,PDGFRA,PDPN,PIM1,PLA2G3,PLA2G4C,PLA2G5,PLIN1,PLK2,PLP1,PMAIP1,PPP1R15A,PRKCD,PRSS23,PTGES,PTGFR,PTPRN,PYCARD,RARA,RBPMS,RCAN2,REL,RELB,RFX2,RGS1,RGS2,RGS20,RGS3,RGS5,RND1,RRAD,RRM1,RRM2,RUNX2,S100A9,SCNN1B,SCO2,SCUBE2,SELL,SELPLG,SERPINB10,SERPINB9,SLC12A1,SLC16A2,SLC1A3,SLC2A4,SLC7A8,SNAI1,SNN,SOCS2,SOCS3,SOX4,SPHK1,ST8SIA4,STMN1,SYNGR3,TAGLN,TBXAS1,TERT,TH,THBD,THBS1,THBS2,TIE1,TK1,TLR2,TLR4,TNC,TNFAIP3,TNFRSF1B,TNFRSF9,TNFSF14,TNFSF15,TNFSF8,TNFSF9,TNNC1,TRAF1,TRAF2,TRAF5,TREM2,TRIM15,TRPC3,TRPC6,TWIST1,TXNRD1,VIP,WNT10B,WNT5A,WNT7A,YY1,ZFP36 | 611 (12)

Table E-7 Top 10 Canonical Pathways Affected by Six-hour Exposure to 20 μM Antimony(III) Potassium Tartrate Trihydrate

Order | Ingenuity Canonical Pathways | -log(P value) | Ratio | Molecules
1 | Agranulocyte Adhesion and Diapedesis | 4.29 | 0.358 | CLDN7,CCL8,SELL,CLDN8,PODXL2,MYH3,CXCR4,IL1RN,CLDN14,C5AR1,MYH11,CXCL1,MYH7,MMP11,MADCAM1,MYL6B,CDH5,CXCL8,IL18,XCL2,CXCR2,SELPLG,IL1A,IL36RN,ITGA4,ACTA1,CXCL3,CD34,CXCL14,MMP1,MMP25,ITGA3,MMP12,ITGB7,CXCL5,CCL4,MMP28,ICAM2,CLDN17,CCL7,CLDN18,CCL1,MMP17,CCL21,CXCL2,MMP7,CCL22,MMP19,CXCL13,MMP20,MMP10,MYH8,MMP14
2 | Granulocyte Adhesion and Diapedesis | 3.79 | 0.35 | CLDN7,CCL8,SELL,CLDN8,CXCR4,IL1RN,CLDN14,C5AR1,CXCL1,MMP11,TNFRSF1B,FPR2,CDH5,CXCL8,HSPB1,IL18,XCL2,CXCR2,SELPLG,IL1A,IL36RN,ITGA4,CXCL3,CXCL14,MMP1,HRH2,MMP25,ITGAM,ITGA3,MMP12,FPR1,HRH4,CXCL5,CCL4,MMP28,ICAM2,CLDN17,CCL7,CLDN18,CCL1,MMP17,CCL21,CXCL2,MMP7,CCL22,MMP19,CXCL13,MMP20,MMP10,MMP14
3 | Eicosanoid Signaling | 3.63 | 0.449 | DPEP3,ALOX12,FPR2,PTGER1,LTB4R2,PLA2G7,PLA2G6,DPEP1,PLA2G3,PLA2G5,PTGER2,PTGIS,PTGFR,PLA2G4C,TBXA2R,PLA2G2E,ALOX12B,PTGES,PTGIR,PTGER3,ALOX15,TBXAS1
4 | Role of Cytokines in Mediating Communication between Immune Cells | 3.28 | 0.444 | IFNA10,IL3,CSF2,IFNG,IL4,IFNA7,IFNA14,CXCL8,IL26,IL18,IL1RN,IL25,IFNA1/IFNA13,IL24,IL1A,IL36RN,IL17A,IFNA16,IFNB1,IFNA4
5 | Role of Hypercytokinemia/hyperchemokinemia in the Pathogenesis of Influenza | 2.91 | 0.447 | IFNA10,IFNG,CCR1,IFNA7,IFNA14,CXCL8,CCR5,IL18,IL1RN,IFNA1/IFNA13,IL1A,IL36RN,IL17A,CCL4,IFNA16,IFNB1,IFNA4
6 | Bladder Cancer Signaling | 2.33 | 0.351 | FGF5,MMP25,FGF1,MMP12,E2F1,THBS1,FGF20,SUV39H1,CDKN1A,MMP28,FGF12,MMP11,FGF21,FGF7,FGF3,FGF2,MMP17,CXCL8,MMP7,MMP19,FGF16,MMP20,MMP10,FGF8,MMP1,FGF9,MMP14
7 | Crosstalk between Dendritic Cells and Natural Killer Cells | 2.24 | 0.346 | CAMK2B,CCR7,IL3,CSF2,IFNG,TREM2,HLA-F,FSCN2,TLR4,CD209,FSCN1,FSCN3,KIR2DL2,TNFRSF1B,PRF1,IL4,LTA,NECTIN2,CD69,IL3RA,KLRD1,IL18,CD40LG,CD28,IFNA1/IFNA13,ACTA1,IFNB1
8 | Role of IL-17A in Psoriasis | 2.2 | 0.583 | S100A9,CXCL1,IL17A,DEFB4A/DEFB4B,CXCL3,CXCL5,CXCL8
9 | Role of Wnt/GSK-3β Signaling in the Pathogenesis of Influenza | 2.1 | 0.362 | IFNA10,IFNG,WNT5A,LEF1,FZD2,WNT5B,IFNA7,IFNA14,FZD7,DVL1,FZD9,WNT2B,WNT11,WNT8B,IFNA1/IFNA13,WNT7A,IFNA16,IFNB1,APC2,IFNA4,WNT10B
10 | Oxidized GTP and dGTP Detoxification | 1.99 | 1 | RUVBL2,NUDT1,DDX6

Pathways 1, 2, 4, 5, 7, 8, and 9 (green background) are related to immune reactions. Pathway 6 (with orange background) is related to cancer. Pathway 10 (with yellow background) is related to oxidative stress.

## E.6 Immune Effects from Compounds Containing Pentavalent Antimony

This appendix lists immune function from compounds containing pentavalent antimony (Table E-8).

Table E-8 Effects of Compounds Containing Pentavalent Antimony on Immunity

Patients, Species, or Experimental System | Antimony Compound | Immune Effects | Functional or Mechanistic Association | Reference
Human studies
Healthy active-duty soldiers treated for leishmaniasis | Sodium stibogluconate | Transient lymphopenia (decreased CD4^+^ and CD8^+^ T cells) | Increased susceptibility to Herpes Zoster infections | Wortmann et al. (1998)
Patients treated for cutaneous leishmaniasis | Glucantime (meglumine antimoniate) | Elevated IL-1β, TNF-α, IL-6 and IL-8 | Amplified pro-inflammatory cytokines upon exposure to antimonials | Kocyigit et al. (2002)
Patients treated for visceral leishmaniasis | Sodium stibogluconate | Elevated IL-1β, TNF-α, IL-6, GM-CSF, and C1q-binding circulating immune complexes (CIC) | Amplified pro-inflammatory cytokines and CIC-induced GM-CSF upon exposure to antimonials | Elshafie et al. (2007)
Animal studies
BALB/c mice | Antimony sodium gluconate | Activation of peritoneal macrophages associated with enhanced antigen presentation to T cells | Increased macrophage membrane fluidity and enhanced antigen presentation capacity | Ghosh et al. (2013)
Normal C57BL/6 mice, IFNγ gene knockout mice, inducible nitric oxide synthase-knockout (iNOS KO) mice, and respiratory burst-deficient gp91^phox−/−^ (X-linked chronic granulomatous disease [X-CGD]) mice | Sodium stibogluconate | In IFNγ gene knockout mice, pentavalent antimony inhibited but did not kill intracellular Leishmania donovani; treatment was effective in killing the parasite in normal, iNOS KO, and X-CGD mice. | Results support a role for T cell-derived IFNγ as a critical host factor required for the efficacy of antimony in promoting parasite killing | Murray and Delph-Etienne (2000)
BALB/c mice | Antimony sodium gluconate | Sodium stibogluconate synergizes with IL-2 to promote IFNγ-dependent anti-Renca tumor immune response | Supports a role for pentavalent antimony in promoting IFNγ-dependent anti-tumor immune response | Fan et al. (2009)
In vitro studies
Murine Baf 3 cell line and TF-1 human myeloid leukemia cells | Sodium stibogluconate | Sodium stibogluconate is a potent inhibitor of protein tyrosine phosphatases including Src homology PTPase1 (SHP-1), SHP-2, and PTP1B | Sodium stibogluconate, which contains a pentavalent antimony atom, (but not antimony(III) potassium tartrate) can alter signaling of multiple cytokines (IL-3, IFNα, and GM-CSF) that signal through receptor tyrosine kinases regulated by PTPases | Pathak and Yi (2001)
Various cancer cell lines | Sodium stibogluconate | Sodium stibogluconate enhanced IFNα-induced Stat1 tyrosine phosphorylation, inactivated intracellular SHP-1 and SHP-2, and induced cellular protein tyrosine phosphorylation in cancer cell lines | Sodium stibogluconate treatment was found to synergize with IFNα to overcome cancer cell lines that were refractory to the anti-cancer effects of IFNα in vitro and in vivo | Yi et al. (2002)
Human CD4+ and CD8+ T lymphocytes from healthy donors and melanoma patients | Sodium stibogluconate | Sodium stibogluconate synergizes with IL-2 to potentiate induction of IFNγ + T cells | Sodium stibogluconate treatment may potentiate T cell function in the presence of IL-2 | Fan et al. (2009)