# Appendix D Animal Study Quality Tables

Table D-1 Schroeder et al. (1970) Study of Male Rats Exposed to Antimony Potassium Tartrate in the Drinking Water

Utility Question | Rating | Rationale
Study design
Randomization | NR | Randomization and initial body weights were not reported.
Controls | +++ | Concurrent control group, exposed to untreated drinking water, had the same number of animals as exposure group did.
Historical data | | No.
Animal model | +++ | Both sexes of a random bred strain, which increases external validity.
Statistical power | +++ | Large numbers of animals (51 males, 59 females) per concentration group were used.
Exposure
Chemical characterization | NR | Not reported, not even purity.
Dosing regimen | ++ | The maximally tolerated dose level was not reached, because the treated group did not show decreased body weight compared to the control group, although the median life spans and longevity (mean age of the last surviving 10%) for both sexes were decreased by the treatment. The dose might not have been high enough to detect neoplastic effects.
Exposure duration | +++ | Though exposure duration was never clearly stated, this study appears to use a lifetime exposure.
Dose-response | + | Only one dose level was tested and no basis for that level was reported. All other elements were administered at the same level, except for lead.
Outcome
Pathology | + | Only grossly visible tumors were reported. The methods stated that gross tumors were fixed but did not state that they were stained or microscopically examined. Consequently, small tumors might have been missed.
Consistency between groups | ++ | A pneumonia epidemic killed many rats and the death rates varied among the groups.
Study duration | +++ | Lifetime study because the animals were observed until their natural death (as compared to scheduled euthanization after a predetermined exposure period).
Confounding
Confounding | ++ | Pneumonia killed various numbers of animals per group, before penicillin treatment controlled the disease. It is unclear that all rats, or only visibly sick rats, received penicillin. Furthermore, the disease might in effect select stronger/healthier animals (than the general population) to complete the study. Additionally, test substance purity was unknown.
Reporting and analysis
Reporting data and statistics | ++ | The statistical methods and results of survival measures were reported, but statistical analysis of tumor incidences was not reported.
Combining lesions | + | Tumors were counted based on gross observation, not histological analysis occurred.

Overall utility: +. The study has low utility because of many limitations, including only reporting grossly visible tumors without organ site or tumor type.

Table D-2 Schroeder et al. (1970) Study of Female Rats Exposed to Antimony Potassium Tartrate in the Drinking Water

Utility Question | Rating | Rationale
Study design
Randomization | NR | Randomization and initial body weights were not reported.
Controls | +++ | Concurrent control group, exposed to untreated drinking water, had the same number of animals as exposure group did.
Historical data | | No
Animal model | +++ | Both sexes of a random bred strain, which increases external validity.
Statistical power | +++ | Large numbers of animals (51 males, 59 females) per concentration group were used.
Exposure
Chemical characterization | NR | Not reported, not even purity.
Dosing regimen | ++ | The maximally tolerated dose level was not reached, because the treated group did not show decreased body weight compared to the control group, although the median life spans and longevity (mean age of the last surviving 10%) for both sexes were decreased by the treatment. The dose might not have been high enough to detect neoplastic effects.
Exposure duration | +++ | Though exposure duration was never clearly stated, this study appears to use a lifetime exposure.
Dose-response | + | Only one dose level was tested and no basis for that level was reported.
Outcome
Pathology | + | Only grossly visible tumors were reported. The methods stated that gross tumors were fixed but did not state that they were stained or microscopically examined. Consequently, small tumors might have been missed.
Consistency between groups | ++ | A pneumonia epidemic killed many rats and the death rates varied among the groups.
Study duration | +++ | Lifetime study because the animals were observed until their natural death (as compared to scheduled euthanization after a predetermined exposure period).
Confounding
Confounding | ++ | Pneumonia killed various numbers of animals per group, before penicillin treatment controlled the disease. It is unclear that all rats, or only visibly sick rats, received penicillin. Furthermore, the disease might in effect select stronger/healthier animals (than the general population) to complete the study. Additionally, test substance purity was unknown.
Reporting and analysis
Reporting data and statistics | ++ | The statistical methods and results of survival measures were reported, but statistical analysis of tumor incidences was not reported.
Combining lesions | + | Tumors were counted based on gross observation, not histological analysis occurred.

Overall utility: +. The study has low utility because of many limitations, including only reporting grossly visible tumors without organ site or tumor type.

Table D-3 Kanisawa and Schroeder (1969) and Schroeder et al. (1968) Study of Male and Female (Combined) Mice Exposed to Antimony Potassium Tartrate in Drinking Water for the Life Span of the Animals

Utility Question | Rating | Rationale
Study design
Randomization | NR | Not reported.
Controls | +++ | Concurrent control group, exposed to doubly deionized water with added essential trace elements, had the same number of animals as the exposure group did.
Historical data | | No
Animal model | +++ | Both sexes of random bred mice were used, giving a high level of external validity.
Statistical power | +++ | A large number (54) of mice per sex per group were used.
Exposure
Chemical characterization | NR | No chemical characterization was reported, not even purity.
Dosing regimen | + | The maximally tolerated dose level was not reached, because the treated group did not show decreased body weight compared to the control group. The dose might not have been high enough to detect neoplastic effects.
Exposure duration | +++ | Mice were exposed for their lifetimes.
Dose-response | + | Only one concentration was tested and no rational for the dose selection was reported. Dose response relationships cannot be evaluated due to only one dose level.
Outcome
Pathology | ++ | Only gross lesions were microscopically evaluated.
Consistency between groups | ++ | The treated and control groups were treated the same while mice were alive. The examination of organs/tissues varied, because only gross lesions (not all major organs) were examined microscopically.
Study duration | +++ | The study duration was lifetime, up to the animals' natural death.
Confounding
Confounding | +++ | Testing substance purity and supplier were unknown. Exposure to antimony via other sources (feed, housing) was negligible because the feed was antimony free and metal exposure via housing was minimized.
Reporting and analysis
Reporting data and statistics | ++ | Although tumor incidents were not statistically analyzed in the study, the data were reported and enabled us to conduct statistical analysis. Statistical methods were described as “numerical data were treated by Chi-squire analysis and by Student’s t test,” but the reported probability in tables did not specify the result was from which method.
Combining lesions | ++ | Tumor incidence was reported for two sexes combined only, instead of male and female separately. Site-specific (lung, liver, mammary gland, and other) information was limited to tumor incidence, with no subtype. Tumors were also grouped by origin (epithelial, non-epithelial) along with being benign or malignant. Overall information did not allow detecting of specific tumor type increase in either sex.

Overall utility: +. Due to many limitations, including only one tested concentration (below maximally tolerated dose), unknown test substance purity, tumor incidences only reported in combined sexes with no histologic information, and lack of site-specific information (except incidences of three sites in sexes combined), this study is of low utility. Data lack sufficient details to allow us to determine whether any specific type of tumor had increased.

Table D-4 NTP (2017a) Study of Male Rats Exposed to Antimony Trioxide by Inhalation for 105 Weeks

Utility Question | Rating | Rationale
Study design
Randomization | +++ | Animals were randomly assigned to groups.
Controls | +++ | Concurrent chamber control was used. Data was also compared with historical control.
Historical data | | Yes
Animal model | +++ | Standard model.
Statistical power | +++ | A large number, 50/sex/group, of animals were used.
Exposure
Chemical characterization | +++ | The chemical and exposure chamber were well characterized, showing high purity, stability, and homogeneity. Concentration inside the exposure chamber was measured in real-time and alarmed if readings were not within limits of acceptable concentrations. Aerosol size, measured monthly, was also consistently <4 μm (MMAD = 1–1.4 μm, GSD 1.8–2.2. Stability in the generation and exposure system was tested before the test, during the test (at 4 weeks for rats), and the end of 2-year study.
Dosing regimen | +++ | Consistent and very close to target concentrations. The highest exposure level was near maximally tolerated levels as evidenced by the trend of decreased survival and a significant decrease in body weight. Neoplasms were significantly increased.
Exposure duration | +++ | Exposure duration was near life span.
Dose-response | +++ | Three dose levels spanning a range of 30-fold were used.
Outcome
Pathology | +++ | Detailed and covering all tissues. Full necropsy with histological exam of all major organs was conducted and verified by an independent quality control pathologist.
Consistency between groups | +++ | Nothing was reported to suggest that animals from different groups were treated differently.
Study duration | +++ | Near life-span study duration was used.
Confounding
Confounding | +++ | No concerns of confounding were reported.
Reporting and analysis
Reporting data and statistics | +++ | Statistical analysis was clearly reported.
Combining lesions | +++ | No indication of concern. Detailed groupings were provided.

Overall utility: +++. There were no concerns of confounding as the chemical was pure, stable, the exposure was well characterized, and all groups were treated the same. The study had a high level of sensitivity to detect neoplasms as it used large numbers of both sexes of rats, exposed at three dose levels, which reached the maximally tolerated level, for a near life-span duration. However, the stock of rat used was new to NTP and so little historical control data existed compared to the previously used Fischer 344 rat stock. Complete necropsies with histological examination of most organs were performed, so the ability to detect neoplasms was high.

Table D-5 NTP (2017a) Study of Female Rats Exposed to Antimony Trioxide by Inhalation for 105 Weeks

Utility Question | Rating | Rationale
Study design
Randomization | +++ | Animals were randomly assigned to groups.
Controls | +++ | Concurrent chamber control was used. Data was also compared with historical control.
Historical data | | No.
Animal model | +++ | Standard model.
Statistical power | +++ | A large number, 50/sex/group, of animals were used.
Exposure
Chemical characterization | +++ | The chemical and exposure chamber were well characterized, showing high purity, stability, and homogeneity. Concentration inside the exposure chamber was measured in real-time and alarmed if readings were not within limits of acceptable concentrations. Aerosol size, measured monthly, was also consistently <4 μm (MMAD = 0.9−1.5 μm, GSD = 1.7−2.1). Stability in the generation and exposure system was tested before the test, during the test (at 4 weeks for rats), and the end of 2-year study.
Dosing regimen | +++ | Consistent, and very close to target, concentrations. The highest exposure level was near maximally tolerated levels as evidenced by the trend of decreased survival and a significant decrease in body weight. Neoplasms were significantly increased.
Exposure duration | +++ | Exposure duration was near life span.
Dose-response | +++ | Three dose levels spanning a range of 30-fold were used.
Outcome
Pathology | +++ | Detailed and covering all tissues. Full necropsy with histological exam of all major organs was conducted and verified by an independent quality control pathologist.
Consistency between groups | +++ | Nothing was reported to suggest that animals from different groups were treated differently.
Study duration | +++ | Near life-span study duration was used.
Confounding
Confounding | +++ | No concerns of confounding were reported.
Reporting and analysis
Reporting data and statistics | +++ | Statistical analysis was clearly reported.
Combining lesions | +++ | No indication of concern. Detailed groupings were provided.

Overall utility: +++. There were no concerns of confounding as the chemical was pure, stable, the exposure was well characterized, and all groups were treated the same. The study had a high level of sensitivity to detect neoplasms as it used large numbers of both sexes of rats, exposed at three dose levels, which reached the maximally tolerated level, for a near life-span duration. However, the stock of rat used was new to NTP and so little historical control data existed compared to the previously used Fisher 344 rat stock. Complete necropsies with histological examination of most organs were performed, so the ability to detect neoplasms was high.

Table D-6 NTP (2017a) Study of Male Mice Exposed to Antimony Trioxide by Inhalation for 105 Weeks

Utility Question | Rating | Rationale
Study design
Randomization | +++ | Animals were randomly assigned to groups.
Controls | +++ | Concurrent chamber control was used. Data was also compared with historical control.
Historical data | | Yes
Animal model | +++ | Standard model.
Statistical power | +++ | A large number, 50/sex/group, of animals were used.
Exposure
Chemical characterization | +++ | The chemical and exposure chamber were well characterized, showing high purity, stability, and homogeneity. Concentration inside the exposure chamber was measured in real-time and alarmed if readings were not within limits of acceptable concentrations. Aerosol size, measured monthly, was also consistently <4 μm (MMAD = 0.9−1.5 μm, GSD 1.7−2.1). Stability in the generation and exposure system was tested before the test, during the test (at 4 weeks for rats), and the end of 2-year study.
Dosing regimen | +++ | Consistent, and very close to target, concentrations. The highest exposure level was near maximally tolerated levels as evidenced by the trend of decreased survival and a significant decrease in body weight. Neoplasms were significantly increased.
Exposure duration | +++ | Exposure duration was near life span.
Dose-response | +++ | Three dose levels spanning a range of 30-fold were used.
Outcome
Pathology | +++ | Detailed and covering all tissues. Full necropsy with histological exam of all major organs was conducted and verified by an independent quality control pathologist.
Consistency between groups | +++ | Nothing was reported to suggest that animals from different groups were treated differently.
Study duration | +++ | Near life-span study duration was used.
Confounding
Confounding | +++ | No concerns of confounding were reported.
Reporting and analysis
Reporting data and statistics | +++ | Statistical analysis was clearly reported.
Combining lesions | +++ | No indication of concern. Detailed groupings were provided.

Overall utility: +++. There were no concerns of confounding as the chemical was pure, stable, the exposure was well characterized, and all groups were treated the same. The study had a high level of sensitivity to detect neoplasms as it used large numbers of both sexes of mice, exposed at three dose levels, which reached the maximally tolerated level, for a near life-span duration. Complete necropsies with histological examination of most organs were performed, so the ability to detect neoplasms was high.

Table D-7 NTP (2017a) Study of Female Mice Exposed to Antimony Trioxide by Inhalation for 105 Weeks

Utility Question | Rating | Rationale
Study design
Randomization | +++ | Animals were randomly assigned to groups.
Controls | +++ | Concurrent chamber control was used. Data were also compared with historical control.
Historical data | | No
Animal model | +++ | Standard model.
Statistical power | +++ | A large number, 50/sex/group, of animals were used.
Exposure
Chemical characterization | +++ | The chemical and exposure chamber were well characterized, showing high purity, stability, and homogeneity. Concentration inside the exposure chamber was measured in real-time and alarmed if readings were not within limits of acceptable concentrations. Aerosol size, measured monthly, was also consistently <4 μm (MMAD = 0.9−1.5 μm, GSD = 1.7−2.1). Stability in the generation and exposure system was tested before the test, during the test (at 4 weeks for rats), and the end of 2-year study.
Dosing regimen | +++ | Consistent, and very close to target, concentrations. The highest exposure level was near maximally tolerated levels as evidenced by the trend of decreased survival and a significant decrease in body weight. Neoplasms were significantly increased.
Exposure duration | +++ | Exposure duration was near life span.
Dose-response | +++ | Three dose levels spanning a range of 30-fold were used.
Outcome
Pathology | +++ | Detailed and covering all tissues. Full necropsy with histological exam of all major organs was conducted and verified by an independent quality control pathologist.
Consistency between groups | +++ | Nothing was reported to suggest that animals from different groups were treated differently.
Study duration | +++ | Near life-span study duration was used.
Confounding
Confounding | +++ | No concerns of confounding were reported.
Reporting and analysis
Reporting data and statistics | +++ | Statistical analysis was clearly reported.
Combining lesions | +++ | No indication of concern. Detailed groupings were provided.

Overall utility: +++. There were no concerns of confounding as the chemical was pure, stable, the exposure was well characterized, and all groups were treated the same. The study had a high level of sensitivity to detect neoplasms as it used large numbers of both sexes of mice, exposed at three dose levels, which reached the maximally tolerated level, for a near life-span duration. Complete necropsies with histological examination of most organs were performed, so the ability to detect neoplasms was high.

Table D-8 Groth et al. (1986) Study of Male Rats Exposed to Antimony Trioxide by Inhalation for 53 Weeks Followed by Post-exposure Observation for 71 to 73 Weeks

Utility Question | Rating | Rationale
Study design
Randomization | NR | Not reported.
Controls | +++ | Concurrent untreated chamber controls (filtered air) were used.
Historical data | | No
Animal model | +++ | Male and female inbred rats were used.
Statistical power | +++ | A large number of rats (90/sex/group) were used.
Exposure
Chemical characterization | ++ | The purity was estimated to be 95.8%, however the authors did not explicitly report the purity of antimony trioxide. The purity of elemental antimony was reported as 80%, and NIH calculated this to mean a purity of antimony trioxide of 95.8%, assuming all of the antimony present was as antimony trioxide. Trace levels of contamination by carcinogens (arsenic and lead) and others (tin, cesium aluminum, and bromine) were not considered to have significantly contributed to carcinogenic effects. The aerosol concentrations didn't reach target levels of 50 mg/m^3^ until after 5 months of adjustment and modifications on the exposure equipment. MMAD of aerosol of 2.80 μm was fine, but the GSD was not reported. Aerosol size appeared only measured once at 6 months of exposure.
Dosing regimen | ++ | The exposure level was based on the middle of the concentration range that workers are exposed to, so it would not be expected to be at the maximally tolerated level. The concentrations fluctuated dramatically, up to 191.1 mg/m^3^ for daily TWAs, while a mean daily TWA was 45, 46 mg/m^3^ (two chambers) and the target concentration was 50 mg/m^3^. It is not clear whether the chamber air was humidified. Survival and body weights were similar to controls, but total neoplasms in the lung were significantly increased over untreated controls.
Exposure duration | ++ | Exposure duration was 53 weeks.
Dose-response | + | Only one exposure level was used, and it was based on the middle of the concentration range that workers are exposed to (i.e., well below animals’ maximal tolerated dose). The actual exposure concentration fluctuated greatly until about 5 months into the study when the target concentration was reached.
Outcome
Pathology | +++ | Most organs were histologically examined.
Consistency between groups | ++ | No indication of differential treatments.
Study duration | ++ | The study duration was 71 to 73 weeks long, roughly 1.4 years, with only 5 months of observation after the end of 53 week-long exposure. These lengths were likely limited because the rats were 8 months old at the beginning of the study.
Confounding
Confounding | + | The chemical was only 80% antimony, with various other metal contaminants, such as tin, lead, cesium, aluminum, arsenic, and bromine. Lead and arsenic are carcinogenic.
Reporting and analysis
Reporting data and statistics | +++ | Statistical analysis was reported for body weights, tissue levels of antimony. Neoplasms were not reported as they were stated to have not occurred.
Combining lesions | +++ | Neoplasms were combined by site. While no numbers of each pathological type were provided, the tumor combining is fine

Overall utility: ++. The chemical was not fully characterized, but was estimated to be 95.8% pure, with trace levels of lead and arsenic as contaminants that were not considered to have significantly contributed to carcinogenic effects. The sensitivity of the study to detect neoplasms was low as only one dose level was used and it was based on the level of exposure to workers and not the maximally tolerated dose. Further, the exposure concentration varied widely until 5 months into the study when the target concentration was reached. The exposure duration was more than a year and full necropsies with histological examinations were performed. Neoplasms were reported with statistical analysis as total neoplasms combined per organ site.

Table D-9 Groth et al. (1986) Study of Female Rats Exposed to Antimony Trioxide by Inhalation for 53 Weeks Followed by Post-exposure Observation for 71 to 73 Weeks

Utility Question | Rating | Rationale
Study design
Randomization | NR | Not reported.
Controls | +++ | Concurrent untreated chamber controls (filtered air) were used.
Historical data | | No
Animal model | +++ | Male and female inbred rats were used.
Statistical power | +++ | A large number of rats (90/sex/group) were used.
Exposure
Chemical characterization | ++ | The purity was estimated to be 95.8%, however the authors did not explicitly report the purity of antimony trioxide. The purity of elemental antimony was reported as 80%, and NIH calculated this to mean a purity of antimony trioxide of 95.8%, assuming all of the antimony present was as antimony trioxide. Trace levels of contamination by carcinogens (arsenic and lead) and others (tin, cesium aluminum, and bromine) were not considered to have significantly contributed to carcinogenic effects. The aerosol concentrations didn't reach target levels of 50 mg/m^3^ until after 5 months of adjustment and modifications on the exposure equipment. MMAD of aerosol of 2.80 μm was fine, but the GSD was not reported. Aerosol size appeared only measured once at 6 months of exposure.
Dosing regimen | ++ | The exposure level was based on the middle of the concentration range that workers are exposed to, so it would not be expected to be at the maximally tolerated level. The concentrations fluctuated dramatically, up to 191.1 mg/m^3^ for daily TWAs, while a mean daily TWA was 45, 46 mg/m^3^ (two chambers) and the target concentration was 50 mg/m^3^. It is not clear whether the chamber air was humidified. Survival and body weights were similar to controls, but total neoplasms in the lung were significantly increased over untreated controls.
Exposure duration | ++ | Exposure duration was 53 weeks.
Dose-response | + | Only one exposure level was used, and it was based on the middle of the concentration range that workers are exposed to (i.e., well below animals’ maximal tolerated dose). The actual exposure concentration fluctuated greatly until about 5 months into the study when the target concentration was reached.
Outcome
Pathology | +++ | Most organs were histologically examined.
Consistency between groups | ++ | No indication of differential treatments.
Study duration | ++ | The study duration was 71 to 73 weeks long, roughly 1.4 years, with only 5 months of observation after the end of 53 week-long exposure. These lengths were likely limited because the rats were 8 months old at the beginning of the study.
Confounding
Confounding | + | The chemical was only 80% antimony, with various other metal contaminants, such as tin, lead, cesium, aluminum, arsenic, and bromine. Lead and arsenic are carcinogenic
Reporting and analysis
Reporting data and statistics | +++ | Statistical analysis was reported for body weights, tissue levels of antimony. Statistical significance was not reported for neoplasm incidences but was calculated by NTP.
Combining lesions | +++ | Neoplasms were combined by site. While no numbers of each pathological type were provided, the tumor combining is fine.

Overall utility: ++. The chemical was not fully characterized, but was estimated to be 95.8% pure, with trace levels of lead and arsenic as contaminants that were not considered to have significantly contributed to carcinogenic effects. The sensitivity of the study to detect neoplasms was low as only one dose level was used and it was based on the level of exposure to workers and not the maximally tolerated dose. Further, the exposure concentration varied widely until 5 months into the study when the target concentration was reached. The exposure duration was more than a year and full necropsies with histological examinations were performed. Neoplasms were reported with statistical analysis as total neoplasms combined per organ site.

Table D-10 Newton et al. (1994) Study of Male Rats Exposed to Antimony Trioxide by Inhalation for 12 Months Followed by Post-exposure Observation for 24 Months

Utility Question | Rating | Rationale
Study design
Randomization | +++ | Used a computer program to randomly sort animals so that mean group weights were comparable.
Controls | +++ | Use concurrent control at the same number of animals as exposure groups.
Historical data | | No
Animal model | +++ | Normal Fischer rats, which are often used in carcinogenicity studies.
Statistical power | +++ | A large number of rats (65/sex/group) were used.
Exposure
Chemical characterization | +++ | A blend of lots from nine producers of antimony trioxide. Highly pure material. Particle size was characterized as having a mass median aerodynamic diameter (MMAD) of 3.76 +/− 0.84 μm and a geometric standard deviation (GSD) of 1.79 +/− 0.32. Exposure concentration was analyzed four times a day and particle sizes were analyzed before the study and every 3 months. Homogeneity of the exposure chamber was verified by measuring 10 different locations.
Dosing regimen | ++ | There were not differences in body weight, survival, or neoplasm incidence, suggesting the dose was not at the maximally tolerated dose.
Exposure duration | +++ | 12-month exposure.
Dose-response | +++ | Three exposed levels were used, which covered a 100-fold range.
Outcome
Pathology | ++ | Only heart, airway, and peribronchial lymph nodes were histologically examined.
Consistency between groups | +++ | Consistent treatment and evaluation of groups.
Study duration | +++ | The study duration was 2 years, with 12 months of exposure and 12 months of observation.
Confounding
Confounding | +++ | Material of high purity. Animal husbandry reported in detail. No significant body weight loss in the treated groups, compared to the control.
Reporting and analysis
Reporting data and statistics | +++ | Since neoplasm incidences were not reported, as they were negative, statistical analysis wasn't reported.
Combining lesions | +++ | No tumor combining, as only three cases [two males (including one from control), one female] were seen.

Overall utility: ++. There was little concern for confounding as the chemical was pure, exposure conditions were well characterized, and groups were treated consistently with animals randomly assigned to exposure groups. The sensitivity of detecting neoplasms was good as high numbers of both sexes were tested. Exposure was at three concentrations for about half a life-span duration (1 year), though observations (1 year) continued to a near life-span duration. However, the highest exposure level did not reach the maximally tolerated level. Most organs were histologically examined, so most neoplasms had the ability of being detected. Although aerosol size was not ideal (slightly over the current upper limit of test guidelines), this paper did show Sb_2_O_3_ accumulation and decreased clearance in the lung (by 80% in the 4.5 mg/m^3^ group). For inert particle, such overload would/could cause lung tumor. The overload was observed at relatively low exposure concentrations (compared to inert particles, such as TiO_2_) and Sb_2_O_3_ toxicity was suspected. It appears conditions that could potentially lead to cancer did persist (Table 9, post-exposure, chronic inflammation in most animals, although hyperplasia was in only very few animals).

Table D-11 Newton et al. (1994) Study of Female Rats Exposed to Antimony Trioxide by Inhalation for 12 Months Followed by Post-exposure Observation for 24 Months

Utility Question | Rating | Rationale
Study design
Randomization | +++ | Used a computer program to randomly sort animals so that mean group weights were comparable.
Controls | +++ | Use concurrent control at the same number of animals as exposure groups.
Historical data | | No
Animal model | +++ | Normal Fischer rats, which are often used in carcinogenicity studies.
Statistical power | +++ | A large number of rats (65/sex/group) were used.
Exposure
Chemical characterization | +++ | A blend of lots from nine producers of antimony trioxide. Highly pure material. Particle size was characterized as having a mass median aerodynamic diameter (MMAD) of 3.76 +/− 0.84 μm and a geometric standard deviation (GSD) of 1.79 +/− 0.32. Exposure concentration was analyzed four times a day and particle sizes were analyzed before the study and every 3 months. Homogeneity of the exposure chamber was verified by measuring 10 different locations.
Dosing regimen | ++ | There were not differences in body weight, survival, or neoplasm incidence, suggesting the dose was not at the maximally tolerated dose.
Exposure duration | +++ | 12-month exposure.
Dose-response | +++ | Three exposed levels were used, which covered a 100-fold range.
Outcome
Pathology | ++ | Only heart, airway, and peribronchial lymph nodes were histologically examined.
Consistency between groups | +++ | Consistent treatment and evaluation of groups.
Study duration | +++ | The study duration was 2 years, with 12 months of exposure and 12 months of observation.
Confounding
Confounding | +++ | Material of high purity. Animal husbandry reported in detail. No significant body weight loss in the treated groups, compared to the control.
Reporting and analysis
Reporting data and statistics | +++ | Since neoplasm incidences were not reported, as they were negative, statistical analysis wasn't reported.
Combining lesions | +++ | No tumor combining, as only three cases [two males (including one from control), one female] were seen.

Overall utility: ++. There was little concern for confounding as the chemical was pure, exposure conditions were well characterized, and groups were treated consistently with animals randomly assigned to exposure groups. The sensitivity of detecting neoplasms was good as high numbers of both sexes were tested. Exposure was at three concentrations for about half a life-span duration (1 year), though observations (1 year) continued to a near life-span duration. However, the highest exposure level did not reach the maximally tolerated level. Most organs were histologically examined, so most neoplasms had the ability of being detected. Although aerosol size was not ideal (slightly over the current upper limit of test guidelines), this paper did show Sb_2_O_3_ accumulation and decreased clearance in the lung (by 80% in the 4.5 mg/m^3^ group). For inert particle, such overload would/could cause lung tumor. The overload was observed at relatively low exposure concentrations (compared to inert particles, such as TiO_2_) and Sb_2_O_3_ toxicity was suspected. It appears conditions that could potentially lead to cancer did persist (Table 9, post-exposure, chronic inflammation in most animals, although hyperplasia was in only very few animals).

Table D-12 Watt (1983) Study of Female Rats Exposed to Antimony Trioxide by Inhalation for One Year Followed by Post-exposure Observation for Two Years

Utility Question | Rating | Rationale
Study design
Randomization | NR | Not reported.
Controls | +++ | Concurrent controls were used, although animals were housed in different rooms (housing chambers separated to control, low concentration, and high concentration). Otherwise, treatments were the same.
Historical data | | No.
Animal model | ++ | Only female rats were used.
Statistical power | + | Small number of animals were used; 13–18 animals per group sacrificed at the end of exposure. Fewer than 10 per group sacrificed between 2 and 12 months post exposure. Fewer than 20 per group sacrificed 12 months post exposure.
Exposure
Chemical characterization | +++ | Detailed chemical analysis verified that Sb_2_O_3_ was of high purity. Small amounts of arsenic (0.02%) and lead (0.2%) were found as contaminates. Dust size (measured by SEM) was reported as Feret diameter. Presumably, this is average from the same particle with rotation. Aerosol concentration in the exposure chamber. The equipment generated aerosols of MMAD <15 μm, but aerosol sizes were not measured. Based on conversion done in Newton et al. (1994) paper Table 2, the MMAD is 5.06 μm, which is above the ideal range of rat inhalation study (no more than 4 μm).
Dosing regimen | +++ | Another potential concern is the use of pine shaving in the exposure chamber. The rats were not in direct contact with shaving, but metabolism change from pine cannot be excluded. This does not affect the interpretation of this study as all groups were treated the same, but has been suggested by Newton et al. (1994) as a factor affecting outcome even though it is based on concerns of increased particulates (rather than rat metabolism). Survival was not reported, but body weight gain was greater than controls, indicating the dose is not close to maximal tolerant dose. Significant increases in neoplasia occurred, indicating the dose level was high enough to cause carcinogenesis.
Exposure duration | +++ | Exposure occurred for up to 1 year, with intermediate sacrifices at 3, 6, 9 months.
Dose-response | ++ | Only two dose levels, ranging over 2.5 folds, were used, limiting the examination of a dose response curve.
Outcome
Pathology | ++ | Major organs were examined microscopically.
Consistency between groups | +++ | Consistent treatment among groups, except housed in different rooms.
Study duration | +++ | The study duration was 2 years, with 1 year of exposure and 1 year of observation.
Confounding
Confounding | ++ | Animals in high dose group were heavier than low dose group at the beginning, suggesting slightly different development level. Not all organs appear to have been examined during necropsy.
Reporting and analysis
Reporting data and statistics | ++ | While statistic methods were not specified, the data were reported with raw numbers and therefore enables statistical analysis.
Combining lesions | +++ | Tumor types were not combined. Scirrhous carcinomas, a pathologically distinctive lung cancer, alone, was significantly increased compared to negative controls.

Overall utility: ++. The chemical purity was high and exposure was characterized, though the particle size (converted by Newton et al. (1994) to be around MMAD 5 μm) was over the recommended (1–4 μm). Only female rats were used, which eliminates the ability to detect sex differences. The sensitivity to detect neoplasms was low as a small number of rats were used at only two dose levels, though the exposure was near life-span duration. The ability to detect neoplasms, if they exist, was moderate as the organs examined during necropsy were not fully reported. The statistical methods used were not reported. The use of large exposure chamber with pigs inside and pine shaving also increased the chance of exposure to non-Sb_2_O_3_ particles (and possible metabolism alternation due to pine shaving and therefore affecting susceptibility).