# Appendix C Human Studies Tables

Table C-1 Evaluation of Selection Bias in Human Cancer Studies

Study | Selection Bias
Jones (1994) | Rating: ++; Direction: ↓ Rationale: Only an external analysis was conducted. Although the impact of healthy worker survivor effect (HWSE) is mitigated by stratification by time since exposure, HWSE is still possible and may bias results toward the null.
Schnorr et al. (1995) | Rating: ++; ↓ Rationale: Only an external analysis was conducted. HWSE was not accounted for in this analysis, which may result in an underestimating of the risk estimates.
Jones et al. (2007) | Rating: ++; ↓ Rationale: Missing death information for 5.7% of untraced individuals would slightly bias results if they experienced the outcome. HWSE was not accounted for in the analyses, however, the impact of the smelter closing during follow-up would reduce the residual survival advantage.
Wingren and Axelson (1993) | Rating: +++; ↔ Rationale: Cases and controls were selected from the same parishes. No evidence suggests that the selection of subjects was related to both antimony exposure and disease.

↓ = results bias toward the null; ↔ = unknown direction of bias.

Table C-2 Evaluation of Exposure Assessment Methods in Human Cancer Studies

Study | Exposure Assessment Rating
Jones (1994) | Rating: ++/+++; Direction: ↔ Rationale: Exposure assessment methods have decent sensitivity and specificity, leading to reliable classification with respect to ever-exposure to antimony and exposure duration. Antimony exposure is assumed based on job description at smelter site.
Schnorr et al. (1995) | Rating: ++; ↓ Rationale: Exposure was reliably characterized as ever-exposure to antimony and duration of antimony exposure, but not with respect to concentration of exposure. Based on the reported environmental sampling data, antimony air exposure varied by plant location and year sampled; however, exposure is not captured at the individual level due to lack of information on job duties, and therefore, may be subject to misclassification.
Jones et al. (2007) | Rating: ++; ↓ Rationale: Given the modeling efforts used to account for the uncertainty in early air contamination levels, and because air sampling concentrations are likely an underestimate of true individual antimony exposure, exposure levels and timing may not represent true antimony concentrations and worker exposure prior to 1972. Authors mention changes in plant processes before NIOSH collected exposure estimates. The 3 scenarios for back-extrapolation (1. twice as high air concentrations in 1937, 2. average concentration from 1937 to 1972, and 3. a doubling in concentrations from 1937 through 1960, then a decrease to 1972 levels) are assumptions based on little empirical data.
Wingren and Axelson (1993) | Rating: +; ↑ Rationale: Exposure to antimony was based on reported job title at death. Those classified as unexposed who may have worked in a glass producing facility or had other antimony occupational exposure over a lifetime may have misclassified exposure. Reported level of antimony used by surveyed glass-working facilities may not represent individual-level exposure to employees. Facility surveys of antimony use was taken at one time point; unknown if antimony use patterns were consistent.

↑ = results bias away from the null; ↓ = results bias toward the null; ↔ = unknown direction of bias.

Table C-3 Evaluation of Outcome Assessment in Human Cancer Studies

Study | Outcome Assessment Rating
Jones (1994) | Rating: +++; Direction: ↔ Rationale: Outcome methods distinguish between diseased and non-diseased subjects. Follow-up and diagnoses are conducted independent of exposure status.
Schnorr et al. (1995) | Rating: +++; ↔ Rationale: Outcome methods distinguish between diseased and non-diseased subjects. Follow-up and diagnoses are conducted independent of exposure status.
Jones et al. (2007) | Rating: +++; ↔ Rationale: Outcome methods distinguish between diseased and non-diseased subjects. Follow-up and diagnoses are conducted independent of exposure status.
Wingren and Axelson (1993) | Rating: ++; ↑ Rationale: Outcome methods distinguish between diseased and non-diseased subjects. Occupational title (i.e., exposure status) was collected from the death and burial register, which noted mortality status. Given the lack of information on the blinding status, diagnostic bias cannot be ruled out. If coder identified diseased subjects as being exposed, it would bias the results away from the null.

↑ = results bias away from the null; ↔ = unknown direction of bias.

Table C-4 Evaluation of Study Sensitivity in Human Cancer Studies

Study | Sensitivity Rating
Jones (1994) | Rating: ++; Direction: ↔ Rationale: Study has few exposed cases but a substantial duration of exposure with a long range for follow-up. Stratification by exposure duration and years increase sensitivity.
Schnorr et al. (1995) | Rating: ++; ↔ Rationale: Study had a small-to-moderate number of exposed cases. There was adequate duration for follow-up, with a substantial duration of exposure. Duration and ever-exposure were measured, but not the range of antimony concentrations.
Jones et al. (2007) | Rating: +; ↔ Rationale: Adequate number of potentially exposed subjects but a small number of exposed cases. Exposure characterized by job-exposure matrix and detailed work histories. Exposure was modeled with a substantial range and level of exposure with adequate duration for latency. However, exposure was not at an individual level and exposure was extrapolated based on assumptions.
Wingren and Axelson (1993) | Rating: +; ↔ Rationale: Study captures variability in antimony use by parish where cases and controls died. However, given the unknown number of exposed subjects, exposed cases, the unknown number of controls, and the unknown individual-level exposure to antimony in glass workers, this study has poor sensitivity.

↔ = unknown direction of bias.

Table C-5 Evaluation of Potential for Confounding Bias for Human Cancer Studies

Study | Confounding Rating
Jones (1994) | Rating: +; Direction: ↑ Rationale: No control for smoking or occupational co-exposures in statistical analysis. Likely co-exposure to arsenic and PAHs (lung carcinogens) based on smelting source materials. Smoking not controlled for, despite high prevalence in the study population.
Schnorr et al. (1995) | Rating: +++; ↔ Rationale: No control for smoking or occupational co-exposures in statistical analysis. Confounding from occupational co-exposures to arsenic and lead are minimal based on source information and environmental testing. Smoking prevalence rates were assumed to be low in this particular population.
Jones et al. (2007) | Rating: ++; ↑ Rationale: No attempt to statistically account for measured occupational co-exposures in analysis. High level of correlation between antinomy, lead, and arsenic air concentrations suggests likely occupational co-exposure. Minimal concern for smoking, but not controlled for in analysis.
Wingren and Axelson (1993) | Rating: +; ↑ Rationale: Smoking and occupational co-exposures lead and asbestos were not statistically controlled for in analysis. Lead and antimony use patterns were highly correlated, and lead was associated with an increased risk of stomach cancer mortality in this population; therefore, risk of confounding bias is high.

↑ = results bias away from the null; ↔ = unknown direction of bias.

Table C-6 Evaluation of Analysis and Selective Reporting for Human Cancer Studies

Study | Analysis Rating | Reporting Rating
Jones (1994) | Rating: +++ Rationale: The study used relevant data and appropriate assumptions and methods of analysis. | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of data that were collected.
Schnorr et al. (1995) | Rating: ++ Rationale: 95% CI are generally favorable to 90% CI regardless of a priori outcome status. | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected.
Jones et al. (2007) | Rating: ++ Rationale: 95% CI are generally favorable to 90% CI regardless of a priori outcome status. | Rating: +++ Rationale: No evidence that reporting of the data or analyses were limited to only a subset of the data that were collected.
Wingren and Axelson (1993) | Rating: ++ Rationale: 95% CI are generally favorable to 90% CI regardless of a priori outcome status. | Rating: ++ Rationale: It is unknown whether reporting was done on only a subset on data. Sample size for cases, controls, and exposure groups were not reported.