# Appendix B ADME Tables

Table B-1 Antimony(III) Trioxide Levels^a^ (μg/g) in Red Blood Cells during a One-year Chronic Inhalation Exposure (after Six Months and 12 Months of Exposure) and a One-year Observation Period (Six Months and 12 Months after Exposure) in Fischer 344 Male and Female Rats

Group | 6 mo | 12 mo | 18 mo (12 mo exposure and 6 mo obs) | 24 mo (12 mo exposure and 12 mo obs)
Males
I- Control | BDL | BDL | 0.17 ± 0.39 | BDL
II- 0.055 mg/m^3^ | 0.53 ± 0.31 | 1.09 ± 0.21 | 0.86 ± 0.68 | BDL
III- 0.51 mg/m^3^ | 5.07 ± 0.29 | 7.55 ± 0.60 | 3.93 ± 0.25 | 2.53 ± 0.27
IV- 4.5 mg/m^3^ | 34.50 ± 3.8 | 70.70 ± 6.3 | 38.60 ± 4.8 | 30.50 ± 7.5
Females
I- Control | BDL | BDL | BDL | BDL
II- 0.055 mg/m^3^ | 0.74 ± 0.06 | 1.48 ± 0.10 | 0.81 ± 0.30 | BDL
III- 0.51 mg/m^3^ | 5.69 ± 0.62 | 9.94 ± 1.32 | 6.53 ± 0.90 | 3.39 ± 0.28
IV- 4.5 mg/m^3^ | 75.60 ± 8.4 | 121.00 ± 10.6 | 74.60 ± 18.3 | 36.60 ± 15.5

Source: Newton et al. (1994).

mo = month; BDL = below detection limit (lowest limit of detection = 0.02 μg of antimony/mL, i.e., 0.024 μg of antimony(III) trioxide/mL); obs = observation

^a^ Total antimony in red blood cells was reported as total antimony(III) trioxide using the relationship 1 mole Sb_2_O_3_ = 1.197 mole Sb_2_.

Table B-2 Blood Antimony Concentrations (μg/g Blood) in Female Rats and Mice Exposed to Antimony Trioxide (N = 5 Except Where Indicated)

| Day 61 | Day 124 | Day 269 | Day 369 | Day 551
Female Mice
Controls | 0.001 ± 0.000 | 0.001 ± 0.001 | 0.001 ± 0.000 | 0.001 ± 0.000 | 0.001 ± 0.000
3 mg/m^3^ | 0.043 ± 0.002** | 0.058 ± 0.001** | 0.053 ± 0.006** | 0.052 ± 0.003** | 0.061 ± 0.010**
10 mg/m^3^ | 0.083 ± 0.002** | 0.089 ± 0.002** | 0.091 ± 0.002** | 0.088 ± 0.003** | 0.087 ± 0.004**
30 mg/m^3^ | 0.141 ± 0.003** | 0.148 ± 0.005** | 0.163 ± 0.008** ^a^ | 0.137 ± 0.007** | 0.163 ± 0.006**^a^
Female Rats
Controls | 0.139 ± 0.012 | 0.050 ± 0.002 | 0.077 ± 0.002 | 0.084 ± 0.008 | 0.066 ± 0.005
3 mg/m^3^ | 7.352 ± 0.375** | 16.135 ± 0.995** | 39.590 ± 3.915** | 50.917 ± 2.296** | 63.297 ± 3.906**
10 mg/m^3^ | 18.079 ± 0.793** | 40.350 ± 1.543** | 88.833 ± 2.210** | 102.083 ± 2.738** | 149.192 ± 8.472**^a^
30 mg/m^3^ | 43.574 ± 1.741** | 96.082 ± 3.940** | 175.437 ± 6.471** | 200.239 ± 10.302** | 231.934 ± 8.681**

Source: NTP (2017a).

** Significantly different (p < 0.01) from the chamber control group by Shirley’s test.

^a^ N = 4.

Table B-3 Tissue Distribution of Antimony (μg Antimony/g Tissue) in Rats after Oral Exposure to Antimony(III) Trioxide by Gavage or in the Diet

Tissue | Controls (M/F)^a^ | 1,000 mg/kg Sb_2_O_3_ Suspension p.o. for 1 Day (M/F)^a^ | 1,000 mg/kg Sb_2_O_3_ Suspension p.o. for 14 Days (M/F)^a^ | 2% Sb_2_O_3_ in Diet^b^ for 49 Days^c^ | 2% Sb_2_O_3_ in Diet^b^ for 8 Months^d^
Thyroid | 0.098/0.195 | 1.507/2.103 | 2.639/2.280 | 88.9 | 156.0
Adrenal | NR | NR | NR | 67.8 | NR
Lung | 0.004/0.002 | 0.041/0.061 | 0.746/0.882 | 14.0 | 3.7
Spleen | 0.010/0.032 | 0.197/0.113 | 1.485/1.386 | 18.9 | 8.1
Heart | 0.004/0.003 | 0.042/0.041 | 0.643/0.356 | 7.6 | 5.1
Kidney | 0.003/0.002 | 0.012/0.023 | 0.323/0.261 | 6.7 | 6.0
Liver | 0.004/0.003 | 0.041/0.064 | 0.823/0.675 | 8.9 | 15.5
Bone marrow | 0.080/0.142 | 1.192/1.996 | 2.486/3.517 | NR | NR
Bone or femur | 0.019/0.010 | 0.048/0.032 | 0.254/0.265 | NR | 2.5
Muscle | 0.003/0.003 | 0.005/0.005 | 0.039/0.044 | NR | 0.3
Whole blood | 0.003/0.003 | 0.708/0.640 | 8.278/6.886 | NR | NR

F = female; M = male; NR = not reported; p.o. = per os (by mouth).

^a^ T. N. O. Quality of Life (2005) as cited by EU (2008).

^b^ Based on consumption of 5 g of food per day per 100 g body weight (Johns Hopkins University 2017), rats exposed to 2% Sb_2_O_3_ in the diet or by gavage at 1,000 mg/kg body weight would be exposed to ~0.1 g per 100 g body weight.

^c^ Westrick (1953).

^d^ Gross et al. (1955) as cited by EU (2008).