# Appendix A Literature Search Strategy

## A.1 Introduction

The objective of the literature search approach is to identify published literature that is relevant for evaluating the potential carcinogenicity of antimony trioxide (https://ntp.niehs.nih.gov/ntp/about_ntp/bsc/2016/december/meetingmaterials/draftantimonytrioxide_508.pdf). The literature search strategy was used to identify publications in the following areas:

- Properties and human exposure (focusing on the U.S. population)
- Disposition (ADME) and toxicokinetics
- Human cancer studies
- Studies of cancer in experimental animals
- Mechanistic data and other relevant effects
  - Genetic and related effects
  - Mechanistic considerations

## A.2 General Approach

Database searching encompasses selecting databases and search terms and conducting the searches. Searches of several citation databases are generally conducted using search terms for antimony, combined with search terms for cancer and/or specific topics, including epidemiological and mechanistic studies. A critical step in the process involves consultation with an information specialist to develop relevant search terms. These terms are used to search bibliographic databases. Table A-1 highlights the general concepts searched and databases consulted. To review all the terms used, please refer to the full search strings in Antimony: RoC Protocol (https://ntp.niehs.nih.gov/ntp/roc/protocols/antimonytrioxide_508.pdf).

Table A-1 Major Topics Searched

Topic | Search Method | Databases Searched
Exposure | Antimony String AND occur*[tiab] | PubMed
Human Studies | Antimony String AND ORoC Epidemiological (Human) Studies Search AND ORoC Cancer Search | PubMed, Scopus, Web of Science
Animal Studies | Antimony String AND Experimental Animals Studies Search AND ORoC Cancer Search | PubMed, Scopus, Web of Science
Mechanism and Genotoxicity | Antimony String AND ORoC Characteristics of Carcinogens Search | PubMed, Scopus, Web of Science

Figure A-1

Literature Search Strategy and Review

## A.3 Search Strategies

Relevant literature is identified using search terms, data sources, and strategies as discussed below.

- General data search: This search covers a broad range of general data sources for information relevant to many or all of the wide range of monograph topics pertaining to antimony.
- Exposure-related data search: This search covers a broad range of potential sources for exposure-related information and physical-chemical properties.
- Database searches in PubMed, Scopus, and Web of Science: The majority of the primary literature used to draft the antimony monograph was identified from searches of these three extensive databases available through the NIEHS Library. Searches for antimony were combined with the search terms for each of the monograph topics listed above to create the specific literature searches.
- Searches for human cancer studies are somewhat unique because they involve the identification of search terms for exposure scenarios that might result in exposure of people to antimony. For antimony, these exposure-related search terms were based on uses of antimony identified from the EPA’s TRI database and the Chemical Data Report rule website.
- QUOSA library of occupational case-control studies search of the QUOSA-based library of more than 6,000 occupational case-control studies, approximately 95% of which are currently available as searchable full-text pdfs, was conducted using the term “antimony.”
- Secondary sources: Citations identified from authoritative reviews or from primary references located by literature search, together with publications citing key papers identified using the Web of Science, “Cited Reference Search,” were also added.

## A.4 Exclusion of Treatment for Leishmaniasis from Human Cancer Searches

The use of antimony for the treatment of leishmaniasis is considered an intentional medical exposure and out of the scope of this monograph. The large corpus of literature related to leishmaniasis treatment was excluded when identifying human studies. Unlike other parts of the monograph, in which leishmaniasis related content was excluded via search terms, the mechanisms section literature search did not exclude leishmaniasis via the use of search terms. The studies on the Leishmania parasite itself were excluded at levels 1 and 2 by reviewers, and studies on the host or cells not infected by leishmaniasis were included for information related to mechanism.

## A.5 Updating the Literature Search

The literature searches were last updated in PubMed, Scopus, and Web of Science on November 13, 2017, prior to submitting the draft monograph for peer review on November 29, 2017. References recommended by the peer reviewers were also considered for the final revisions.

## A.6 Review of Citations Using Web-based Systematic Review Software

Citations retrieved from literature searches were uploaded to web-based systematic review software and screened using inclusion and exclusion criteria. Multi-level reviews of the literature were conducted, with initial reviews (Level 1) based on titles and abstracts only to identify citations that could be excluded and to assign the included literature to one or more monograph topics; subsequent reviews (Level 2) for literature assigned to the various monograph topics (Exposure, ADME & TK, Human cancer studies, etc.) were based on full-text (i.e., PDFs) of the papers and were carried out by the writer and scientific reviewer for each monograph section. Two reviewers, at least one of whom is a member of the ORoC at NIEHS, participated at each level of review.