# 8 Overall Cancer Evaluation and Preliminary Listing Recommendation

The purpose of this monograph is to assess the carcinogenicity data for 13 haloacetic acids found as water disinfection by-products and to determine whether the scientific evidence meets the RoC criteria for listing as a class, subclasses, or as individual haloacetic acids. The overall evaluation integrates the assessments of the animal cancer studies (Section 4, Section 8.1), mechanistic and other relevant data (Section 6, Section 8.2), as well as the read-across analysis for evaluating haloacetic acids as a class or subclasses, to reach preliminary listing conclusions (see Figure 1 in Methods section).

Overall, the data from cancer studies in humans are inadequate to evaluate the relationship between human cancer and exposure specifically to the individual haloacetic acids, subclasses of haloacetic acids, or haloacetic acids as a class, as only one study was identified that provided risk estimates specific for a class of, or for individual haloacetic acids. However, studies on water disinfection by-products suggest the potential for cancer risk from chlorinated water and increase the confidence of the relevance of the animal cancer studies (conducted at higher doses) to humans.

## 8.1 Evidence of Carcinogenicity from Studies in Experimental Animals

There is sufficient evidence of carcinogenicity for dichloroacetic acid, dibromoacetic acid, bromochloroacetic acid, and bromodichloroacetic acid from studies in experimental animals.

The conclusion for each of these haloacetic acids is based on significantly increased incidences of malignant tumors or a combination of benign and malignant tumors at several organ sites in rodents or in several species by exposure in drinking water (see Section 4, Table 4-1 and Table 4-3, and Table 8-1 below). Exposure to dichloroacetic acid induced liver tumors (hepatocellular adenoma and carcinoma) in male Fischer 344 rats and in male and female B6C3F_1_ mice. Exposure to dibromoacetic acid, bromochloroacetic acid, and bromodichloroacetic acid induced liver tumors (hepatocellular adenoma, carcinoma) in both sexes and hepatoblastoma in male B6C3F_1_ mice and tumors at other sites in male and female Fischer 344 or Fischer 344N/Tac rats (for bromodichloroacetic acid). These three haloacetic acids all induced malignant mesothelioma in male rats and bromochloroacetic acid and bromodichloroacetic acid induced mammary gland tumors (fibroadenoma, carcinoma) in female rats. Bromodichloroacetic acid exposure also resulted in malignant skin tumors in male rats. Bromochloroacetic acid induced tumors in the large intestine in both sexes of rats. Although the large intestinal tumors were adenoma, they are considered to be supportive of a carcinogenic response because of their rarity and progression to malignant tumors. Dibromoacetic acid also induced lung tumors (alveolar/bronchiolar carcinoma) in male B6C3F_1_ mice and bromodichloroacetic acid induced Harderian gland (benign or malignant) tumors in male rats.

Table 8-1 Evidence of Cancer in Experimental Animals

Neoplasm or Tissue | DCA | | | | DBA | | | | BCA | | | | TCA | | | | BDCA
Neoplasm or Tissue | Rats | | Mice | | Rats | | Mice | | Rats | | Mice | | Rats | | Mice | | Rats | | Mice
Neoplasm or Tissue | M | F | M | F | M | F | M | F | M | F | M | F | M | F | M | F | M | F | M | F
Liver | X | – | X | X | – | – | X | X | – | – | X | X | – | – | X | X | – | – | X | X
Mononuclear-cell leukemia | – | – | – | – | – | X | – | – | – | – | – | – | – | – | – | – | – | – | – | –
Malignant mesothelioma | – | – | – | – | X | – | – | – | X | – | – | – | – | – | – | – | X | – | – | –
Mammary gland | – | – | – | – | – | – | – | – | – | X | – | – | – | – | – | – | – | X | – | –
Lung | – | – | – | – | – | – | X | – | – | – | – | – | – | – | – | – | – | – | – | –
Skin | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | X | – | – | –
Harderian gland | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | – | X | –
Large intestine | – | – | – | – | – | – | – | – | X | X | – | – | – | – | – | – | – | – | – | –

DCA = dichloroacetic acid, DBA = dibromoacetic acid, BCA = bromochloroacetic acid, TCA = trichloroacetic acid, BDCA = bromodichloroacetic acid.

The evidence of carcinogenicity from studies in experimental animals is not sufficient to meet the RoC criteria for listing monochloroacetic acid, monoiodoacetic acid, or trichloroacetic acid (TCA). Exposure to monochloroacetic acid by gavage did not induce tumors in male and female B6C3F_1_ mice or Fischer 344 rats. Monoiodoacetic acid applied dermally in a co-carcinogen study with 7,12 dimethylbenz[a]anthracene (DMBA) in mice (strain and sex not given) resulted in papillomas. In addition, monoiodoacetic acid transformed NIH3T3 cells in a cell transformation assay that resulted in aggressive fibrosarcomas after injection into Balb/c mice. Exposure to trichloroacetic acid in drinking water induced liver tumors in male and female B6C3F_1_ mice but not in male F344 rats (female rats not tested) and did not induce tumors in male mice with intraperitoneal injection. No cancer studies in experimental animals were available for monobromoacetic acid, diiodoacetic acid, chloroiodoacetic acid, bromoiodoacetic acid, tribromoacetic acid, and chlorodibromoacetic acid.

## 8.2 Summary of Mechanistic Data and Read-across Approach

Key mechanistic cancer-initiating events are not known for the HAAs but most likely involve multiple biochemical pathways as several potential molecular initiating events have been identified. The selected haloacetic acids may induce cancer through binding to macromolecules, for example, causing oxidative stress through perturbation of energy metabolism within the cell or affecting regulation of genes involved in carcinogenicity.

Haloacetic acids did not form a category to evaluate as a class or a subclass because of lack of a well-defined mechanism or mode(s) of action and lack of a clear trend in carcinogenic potency. QSAR model predictions of cancer potency were not consistent with cancer data. Therefore, the current data are inadequate to support considering haloacetic acids as a chemical class or subclass.

## 8.3 Preliminary Listing Recommendation

These preliminary listing recommendations are based on applying the RoC listing criteria (https://ntp.niehs.nih.gov/go/rocprocess) to the body of scientific evidence provided in this monograph.

Dichloroacetic acid, dibromoacetic acid, chlorobromoacetic acid, and bromodichloroacetic acid are reasonably anticipated to be human carcinogens based on sufficient evidence from studies in experimental animals and supporting mechanistic data that demonstrate biological plausibility of its carcinogenicity in humans.

- Dichloroacetic acid – liver tumors (male and female mice, male rats)
- Dibromoacetic acid – liver tumors (male and female mice), malignant mesothelioma (male rats), mononuclear-cell leukemia (female rats), lung tumors (male mice)
- Bromochloroacetic acid – liver tumors (male and female mice), malignant mesothelioma (male rats), mammary gland tumors (female rats), large intestinal tumors (male and female rats)
- Bromodichloroacetic acid – liver tumors (male and female mice), Harderian gland tumors (male mice), malignant mesothelioma and skin tumors (male rats), and mammary gland tumors (female rats)

Chlorodibromoacetic acid is reasonably anticipated to be human carcinogen based on (1) metabolism studies that provide convincing evidence that chlorodibromoacetic acid is metabolized to bromochloroacetic acid, (2) sufficient evidence for the carcinogenicity of bromochloroacetic acid from studies in experimental animals, and (3) supporting mechanistic data that demonstrate biological plausibility of its carcinogenicity in humans. These mechanisms are biologically plausible in humans.

Tribromoacetic acid is reasonably anticipated to be a human carcinogen based on (1) metabolism studies that provide convincing evidence that tribromoacetic acid is metabolized to dibromoacetic acid, (2) sufficient evidence for the carcinogenicity of dibromoacetic acid from studies in experimental animals, and (3) supporting mechanistic data that demonstrate biological plausibility of its carcinogenicity in humans. These mechanisms are biologically plausible in humans.

Distribution and mechanistic information relating to properties of carcinogens for almost all of the 13 HAAs is available (see Section 6); however, the data are inadequate to group all 13 haloacetic acids as a class or into subclasses based on the type and number of halogens.