# 7 Evaluation of Haloacetic Acids as a Class or Subclass(es)

Since only 6 of the 13 haloacetic acids considered in this monograph have been tested for carcinogenicity in experimental animals, the primary purpose of this section is to evaluate whether or not the carcinogenic potential of any or all of the haloacetic acids that have not been tested in long-term animal cancer bioassays could be reasonably predicted based on application of read-across-like principles and methods. The key questions addressed in this section are as follows:

1. Can haloacetic acids be evaluated as a class or subclass(es) for potential carcinogenicity based on a common mode(s) of carcinogenic action or key intermediate events that are relevant to carcinogenicity?
2. Can a read-across (e.g., QSAR) model and/or other models help inform the evaluation of the carcinogenicity of haloacetic acids that do not have animal carcinogenicity studies?

## 7.1 Approach and Methods

A read-across-like approach was used to determine whether haloacetic acids could be evaluated as a class or subclass(es) or if this approach could be applied to individual haloacetic acids that do not have cancer data. Read-across is a data gap-filling technique used with an analogue or category (group of chemicals whose physico-chemical, metabolic, and toxicological properties are likely to be similar or follow a regular pattern based on structural similarity) approach (ECHA 2008; Patlewicz et al. 2015). In the read-across approach, endpoint information for a tested chemical (source) is used to predict the same endpoint for another chemical (target) which is considered similar (Patlewicz et al. 2015; Schultz et al. 2015). Haloacetic acids as a class were judged to fit the general definition of a chemical category based on chemical structure, properties, and generally consistent patterns in toxicokinetics and toxicology. OECD (2017) defines a chemical category as, “a group of chemicals whose physicochemical and human health and/or ecotoxicological properties and/or environmental fate properties are likely to be similar or follow a regular pattern, usually as a result of structural similarity.” In this context, the use of a read-across-like approach is intended to predict carcinogenicity for haloacetic acids that have not been tested in a cancer bioassay.

Two general approaches are described here: (1) a category approach in which a group of haloacetic acids, consisting of either all 13 molecules or a chemically defined subclass with fewer haloacetic acids can be evaluated together, and (2) evaluation of individual haloacetic acids using metabolism data and/or an analogue approach. The first approach would use basic read-across-like methods to determine if data gaps can be filled and would include an evaluation of all the relevant data presented in the previous sections of this monograph to determine if it is feasible to consider all haloacetic acids or a specific subclass of haloacetic acids as a category based on carcinogenicity (Section 7.2). The second approach will determine if individual haloacetic acids (without cancer data) could be evaluated as metabolites and/or with an analogue approach to read-across based on similar metabolic pathways and toxicokinetic data when compared to related chemicals (i.e., analogues) with cancer data (Section 7.3). The methods for the two variations of the category approach are described below in Sections 7.1.1 for all 13 haloacetic acids and 7.1.2 for potential subclasses, and the methods for the analogue approach are described in Section 7.1.3. The application of the category approach for all 13 haloacetic acids is discussed in Section 7.2, that for a subclass of haloacetic acids in Section 7.3, and the analogue approach in Section 7.4.

### 7.1.1 Approach for Evaluating Haloacetic Acids as a Class

The primary methods for the read-across-like approach for evaluating haloacetic acids as a class include (1) a comparison of the mechanistic data based on the characteristics of carcinogens across the different haloacetic acids, (2) an assessment of QSAR evaluations of haloacetic acids reported in the literature for biological effects, and (3) a comparison of cancer potency using QSAR modeling and reported animal cancer data for haloacetic acids.

The general trends in potency estimates for various mechanistic endpoints and chemical properties of the 13 haloacetic acids are shown in a heat map in Table 7-1, which summarizes data previously described in Section 1 (chemical properties), Section 3 (toxicokinetics), Section 4 (animal carcinogenicity), and Section 6 (mechanistic and other relevant data) that provide information potentially related to toxicity and carcinogenicity of HAAs. This table includes toxicokinetic data, physicochemical properties (pK_a_, E_LUMO_, and binding affinity for proteins and DNA), in vitro and in vivo data for several key events potentially associated with carcinogenicity (see Section 6, Figure 6-6), and animal carcinogenicity (see Section 4). Each row in the table is independently scored and ranked on a color scale with darker to lighter shades indicating high to low value or potency, white representing negative (N) results, and gray denoting no data. Most of the data in Table 7-2 were derived from the potency estimates discussed in Section 6 and tabulated in Appendix D.

Table 7-1 Comparison of Relative Potency Estimates for Mechanistic Endpoints and Chemical Properties of Haloacetic Acids

Endpoint | Monohaloacetic Acids | | | Dihaloacetic Acids | | | | | | Trihaloacetic Acids
Endpoint | CA | BA | IA | DCA | DBA | DIA | BCA | CIA | BIA | TCA | TBA | BDCA | CDBA
Toxicokinetics^a^
Oral bioavailability (%) | 100 | | | 81 | 30 | | 47 | | | 100 | 62 | 96 | 100
Unbound fraction (%) | 27 | | | 94 | 89 | | 93 | | | 53 | 18 | 49 | 55
Total clearance (mL/kg/h) | 262 | | | 267 | 491 | | 1037 | | | 92.5 | 754 | 286 | 486
Renal (% of total) | 59 | | | 1.1 | 2.6 | | 3.6 | | | 45.5 | 22.7 | 31.1 | 37.4
Nonrenal (% of total) | 41 | | | 98.9 | 97.4 | | 96.4 | | | 54.5 | 77.2 | 68.9 | 62.6
Chemical properties^b^
pK_a_ | 2.97 | 2.96 | 2.95 | 1.41 | 1.39 | | 1.4 | 1.47 | 1.67 | 0.66 | 0.03 | 0.05 | 0.04
E_LUMO_ (deprotonated) | 9.43 | 8.68 | 7.18 | 8.44 | 7.51 | | 7.78 | 6.40 | 6.46 | 7.13 | 6.12 | 6.65 | 6.42
TR_GSH_ | 0.71 | 2.18 | 2.15 | 1.68 | 1.48 | | 1.93 | 1.35 | 0.62 | 1.01 | 2.26 | 1.56 | 1.1
TR_DNA_ | 0.92 | 0.84 | 0.81 | 0.5 | 1.9 | | 3.18 | 1.17 | 1.47 | 0.99 | 2.61 | 0.73 | 0.95
Oxidative stress in vitro^c^
AREc32 | 3.7 | 192 | 278 | 0.17 | 8.3 | | 7.1 | 45.5 | 38.5 | N | 2.3 | 0.5 | 0.2
ARE-bla | 4 | 90.9 | 196 | 0.06 | 4 | | 2.2 | 10 | 18.9 | N | 1.5 | 0.25 | 0.46
Oxidative stress in vivo^d^
8-OHdG | | | | 1.4 | 2.9 | | 2.9 | | | 1.2 | | 1.7
TBARS | | | | 129 | 250 | | 290 | | | 67 | | 240
Genetox in vitro
SOS-umuC^c,e^ | 60 | 2400 | 15400 | 180 | 2564 | | 2941 | 5263 | 9091 | 60 | 142860 | 9091 | 9091
Ames TA100 (-S9)^f^ | 44 | 6588 | 14129 | 36 | 183 | | | | | N | N
Ames TA100 (-S9)^g^ | | | | 5.2 | 61.9 | | 60.6 | | | N | 1.2 | 31.6 | 1.7
Comet CHO cells^h^ | 2439 | 58820 | 114900 | N | 556 | 500 | 333 | | 313 | N | 400 | N | 71
HGPRT CHO cells^i^ | 8.7 | 14.6 | 836 | 2.8 | 66.2 | | | | | N
P53-bla^c^ | 5882 | 105260 | 212770 | N | 3846 | | 4348 | 9091 | 9091 | N | N | N | N
Genetox in vivo^j^ | | | | 0.5 | 1 | | N | | | N | | N
PPARα in vitro^k^ | 2 | 20 | 100 | 1 | 1 | | | | | 2 | 1
PPARα in vivo^l^ | N | | | 2 | 3.5 | | N | | | 4.3 | | N
GST-ζ inhibition^m^ | | | | 45 | 83 | | 81 | | | N
Animal carcinogenicity
Species/tumor site^n^ | N | | | 2 | 3 | | 3 | | | 1 | | 3
TD_50_s rat (predicted)^o^ | 0.0041 | 0.0025 | 0.0015 | 0.0071 | 0.0029 | 0.0012 | 0.0044 | 0.0028 | 0.0019 | 0.0076 | 0.0027 | 0.0052 | 0.0037
TD_50_s mouse (predicted)^o^ | 0.0021 | 0.0012 | 0.0007 | 0.0024 | 0.0011 | 0.0004 | 0.0016 | 0.0010 | 0.0007 | 0.0027 | 0.0011 | 0.0019 | 0.0014
BMDL^p^ | | | | 0.49 | 0.04 | | 0.08 | | | 0.67 | | 0.06

Darker to lighter shade = high to low value or potency, white = negative (N), gray = no data.

^a^ Schultz et al. (1999) (di- and trihaloacetic acids), Kaphalia et al. (1992); Saghir et al. (2001); Saghir and Rozman (2003) (chloroacetic acid, high doses).

^b^ pK_a_ = the negative log of the acid dissociation constant (lower pK_a_ indicates stronger acid and greater dissociation at physiological pH); E_LUMO_ = energy of the lowest unoccupied molecular orbital (lower value indicates softer electrophile); TR = toxicity ratio (TR_GSH_ > 1.2 suggest the compound is a soft electrophile and preferentially reacts with protein, TR_DNA_ > 1.2 indicates hard electrophile and preferentially reacts with DNA, both values >1.2 indicates unspecific reactivity) (Stalter et al. 2016a).

^c^ 1/EC_IR1.5:_ Effective concentration that elicits an induction ratio of 1.5 (i.e., 1.5-fold or 50% effect increase compared to the control) (Stalter et al. 2016a).

^d^ 8-OHdG/10^5^ dG liver, TBARS: nmol malondialdehyde/g liver (Austin et al. 1996; Larson and Bull 1992).

^e^ 1/EC_IR1.5_ (Stalter et al. 2016a; Zhang et al. 2016).

^f^ Revertants/µmol, adjusted for cytotoxicity where reported (Kargalioglu et al. 2002; Plewa et al. 2004b).

^g^ Revertants/µmol (CEBs database). Note: CEBS data are not directly comparable to Plewa et al. (2004b) and Kargalioglu et al. (2002) because of different methods.

^h^ 1/genotoxic potency (i.e., HAA concentration calculated using regression analysis at the midpoint of the curve within a concentration range that expressed >70% cell viability) (Plewa et al. 2010).

^i^ Mutant frequency/mM (Zhang et al. 2010).

^j^ 1 = positive, 0.5 = weak positive, 0 = negative (IARC 2013a; 2013b; 2014a; 2014b; NTP 2007b; NTP 2009; NTP 2015).

^k^ 1/LEC (lowest effective concentration) (Walgren et al. 2004).

^l^ Fold increase compared to control (Acyl-CoA- oxidase activity (DeAngelo et al. 1989; NTP 2015; Parrish et al. 1996; Xu et al. 1995).

^m^ % reduction enzyme activity compared to controls (Anderson et al. 1999; Gonzalez-Leon et al. 1999).

^n^ N = no evidence of carcinogenicity, 1 = liver tumors in mice only, 2 = liver tumors in rats and mice, 3 = multiple tumor sites in rats and mice.

^o^ ADMET Predictor™ software.

^p^ Reciprocal (1/mg/kg/day for Benchmark dose low (BMDL) values (EPA at https://www.epa.gov/iris and CEBS at https://tools.niehs.nih.gov/cebs3/ui/).

Table 7-2 Evaluation of Subclasses of Haloacetic Acids

Subclass | Members^a^ | Confidence for Potential Category | Rationale
Monohaloacetic acids | CA, BA, IA | No | CA tested negative in a long-term cancer bioassay. IA was positive in the cell transformation assay. Insufficient data to read-across to BA or IA.
Dihaloacetic acids | DCA, DBA, DIA, BCA, CIA, BIA | Low | DCA, DBA, and BCA are rodent carcinogens and are potential analogues for read-across to the iodinated compounds; however, greater uncertainty regarding impact of iodine substitution on carcinogenicity.
Trihaloacetic acids | TCA, TBA, BDCA, CDBA | Low | TCA and BDCA tested positive in cancer bioassays. TCA may cause liver cancer via different mechanisms than other haloacetic acids. Potential analogues: BDCA could be used as an analogue for potential read-across to CDBA, which is also metabolized to BCA. There is more uncertainty with read-across to TBA.
Chlorinated acetic acids | CA, DCA, BCA, CIA, TCA | No | All but CIA have been tested in long-term cancer bioassays; however, the negative findings of CA in cancer studies present a challenge for read-across, and result in increased uncertainty. Potential analogues: BCA could be a potential analogue for read-across to CIA.
Brominated acetic acids | BA, DBA, BCA, BIA, TBA, BDCA, CDBA | Maybe Low/moderate | DBA, BCA, and BDCA are rodent carcinogens. TBA is metabolized to DBA and CDBA is metabolized to BCA. The uncertainty for this subclass is based on lack of carcinogenicity with CA and a possible unique mode of action for the monohaloacetic acids. Potential analogues: BCA is a potential analogue for read-across to BIA, but more uncertainty as noted above. BDCA is a potential analogue for read-across to CDBA, which is also metabolized to BCA.
Iodinated acetic acids | IA, DIA, CIA, BIA | No | None of the members have been tested in a long-term cancer bioassay. The modes of action may not be the same for the mono- and dihaloacetic acids containing iodine.
Brominated di- and trihaloacetic acids | DBA, BCA, BIA, TBA, BDCA, CDBA | Moderate | DBA, BCA, and BDCA are rodent carcinogens. Based on similarity of tumor profiles and trends in metabolism, toxicokinetics, physicochemical properties, and potential key events, the mode of action for this subclass is possibly similar. However, the similarities are greater within the dihalo- and trihaloacetic acids than across these molecules. Potential analogues: TBA is metabolized directly to DBA and CDBA is metabolized to BCA. In addition, BDCA is a potential analogue for read-across to both CDBA and TBA. Read-across to BIA is more uncertain as noted above.

CA = chloroacetic acid; BA = bromoacetic acid; IA = iodoacetic acid; DCA = dichloroacetic acid; DBA = dibromoacetic acid; BCA = bromochloroacetic acid; DIA = diiodoacetic acid; CIA = chloroiodoacetic acid; BIA = bromoiodoacetic acid; TCA = trichloroacetic acid; TBA = tribromoacetic acid; BDCA = bromodichloroacetic acid; CDBA = chlorodibromoacetic acid.

Carcinogenic potency was assessed using two quantitative measures (both expressed as mg/kg body weight per day) – a QSAR model for predicting TD_50_ values (chronic dose rate that would induce tumors in half the animals tested) and benchmark doses (BMDs) as 95% lower confidence corresponding to a 10% response level (BMDLs). The TD_50_ values were predicted for all 13 haloacetic acids using a readily available open source QSAR model, the ADMET Predictor™ version 7.2 chronic carcinogenicity model (https://www.simulations-plus.com/software/admet-property-prediction-qsar/), for both rats and mice based on the parent compound structure and default settings. BMDL values for trichloro- and dichloroacetic acids were available from EPA’s Integrated Risk Information System (IRIS) database (available at https://www.epa.gov/iris) and BMDL values for combined liver tumors in male mice (dibromo-, bromochloro-, and bromodichloroacetic acid were available from NTP studies (CEBS database available at https://cebs.niehs.nih.gov/multistage/). Predicted BMDLs and estimated TD_50_s (reported as reciprocals) are included in Table 7-1.

In addition, a subjective measure of carcinogenic potency was derived from the results of the animal cancer bioassays and results are included in Table 7-1. Values of 0 to 3 were assigned as follows: N = negative response, 1 = liver tumors in mice only, 2 = liver tumors in mice and rats, and 3 = liver and other tumor sites in rats and mice.

### 7.1.2 Approach for Evaluating Subclasses of Haloacetic Acids

The approach for evaluation of subclasses of haloacetic acids is essentially the same as for the set of 13 haloacetic acids, but by making subclasses based on similar chemical structures, e.g., number of halogens or type of halogen substitutions, it might be possible to apply the read-across-like methods described above to a set of molecules with more consistent chemical characteristics.

### 7.1.3 Approach for Evaluating Haloacetic Acids for a Potential Analogue Approach

The approach for identifying potential analogues among haloacetic acids uses one molecule with tumorigenicity data as a source chemical to inform the potential tumorigenicity of a second haloacetic acid that has not been tested in a cancer bioassay. Reasons for selecting a source chemical or chemicals for a target haloacetic acid include metabolism, which could provide direct evidence that the tumorigenic source chemical is metabolized to the target chemical and similarities of physicochemical properties that are related to potential key events in carcinogenicity (see Table 7-2).

## 7.2 Evaluation of Haloacetic Acids as a Class

Overall, studies of metabolism, clearance, cytotoxicity, genotoxicity, and other non-cancer adverse effects among the haloacetic acids provide some evidence that haloacetic acids could be considered as a class or subclass. As mentioned in Section 6, the haloacetic acids are generally considered soft electrophiles and the likely molecular initiating event is reaction with protein sulfhydryl groups. Reaction with proteins can cause indirect genotoxicity through generation of reactive oxygen species (ROS) (Stalter et al. 2016a). The available studies found a strong relationship for greater toxic potency with larger halogen size (i.e., iodo- > bromo- ≫ chloro-) and decreasing toxicity with an increasing degree of halogenation (i.e., mono- > di- > tri-) (see Table 7-1). There are some exceptions to the general trends (e.g., trichloroacetic acid is the strongest PPARα agonist while dichloroacetic acid shows low activity for many of the key events). In cases where data were available for only a few of the haloacetic acids (e.g., GST-ζ inhibition, in vivo genetic effects, or oxidative stress), the trends are not as evident because of incomplete data.

QSAR techniques have also successfully predicted several biological properties of the haloacetic acids as a category and have established similarity patterns among these chemicals. Two independent in vitro studies investigated different biological effects (oxidative stress and genotoxicity, and neural tube defects in mouse embryo cultures) of the haloacetic acids and reported that although the relative potency of the mono-, di-, and trihaloacetic acids was not highly correlated with any single property, there was a strong correlation when two chemical properties were considered together as independent variables: energy of the lowest unoccupied molecular orbital (E_LUMO_) and the acid dissociation constant (pK_a_) (Richard and Hunter 1996; Stalter et al. 2016a). A series of QSAR models further indicated that these two molecular parameters account for two opposing trends in the data: E_LUMO_ was related to the intrinsic reactivity and correlated with increasing potency with halogen size, especially among the monohaloacetic acids. On the other hand, pK_a_ was related to transport and bioavailability and correlated with decreasing potency with an increasing degree of halogenation within a series (i.e., bromo- > dibromo- > tribromoacetic acid) and increasing potency with halogen size among the di- and trihaloacetic acids (Richard and Hunter 1996). Related parameters that have shown moderate to strong correlations with cytotoxicity and/or genotoxicity of haloacetic acids include the log octanol/water partition coefficient (log K_ow_), carbon-halogen bond length, and relative SN2 reactivity (Pals et al. 2011; Plewa et al. 2010; Plewa et al. 2004b).

Although the data show consistent trends in potency for many of the potential key events involved in the toxicity of these compounds, their relationship to carcinogenic potency is unknown. In addition, the available carcinogenicity data do not appear to support evaluating haloacetic acids as a class. Using a subjective measure of carcinogenicity (described above), the trend observed with the carcinogenicity data is somewhat consistent with the trends observed with other endpoints (i.e., brominated > chlorinated forms and dichloroacetic acid > trichloroacetic acid) but does not distinguish between di- or trihaloacetic acids containing at least one bromine atom. Moreover, chloroacetic acid also presents a challenge because the data do not explain the absence of rodent carcinogenicity when this compound shows a greater or similar genotoxic and oxidative stress potency than the di- or trihaloacetic acids. However, the maximum dose tested by oral exposure in mice was much lower (100 mg/L) than that used for the other tested haloacetic acids (at least 1,000 mg/L) because of high toxicity of chloroacetic acid. The estimated TD_50_s and published BMDLs for carcinogenicity do not follow these general trends. The QSAR predicted TD_50_s for carcinogenicity of all 13 haloacetic acids based on structural attributes and default settings that were within one order of magnitude of each other, did not predict that chloroacetic acid would be inactive as a rodent carcinogen, and predicted that trichloroacetic acid was the most potent. The published BMDL values (liver tumors in male mice) for dichloro-, dibromo-, bromochloro-, trichloro-, and bromodichloroacetic acid ranged from 1.5 to about 25 mg/kg/day, thus, they do not provide sufficient separation to determine a potency trend with any degree of confidence and also indicated that trichloroacetic acid was the most potent. In addition, the mechanisms by which haloacetic acids induce carcinogenic effects in experimental animals have not been conclusively determined and remain as a large source of uncertainty for read-across, especially for an apical endpoint as complex as carcinogenicity. There is also evidence that, at least for dichloroacetic acid and trichloroacetic acid, the modes of action are likely different based on species affected and dose response of tumor formation, liver tumor mutation spectra, toxicokinetics, PPARα activation, liver pathology, and tumor phenotypes (Anna et al. 1994; Bull 2000; Bull et al. 2002; Bull et al. 1990; Corton 2008; Ferreira-Gonzalez et al. 1995; Pereira and Phelps 1996; Stauber et al. 1998).

Based on the lack of a well-defined mechanism or mode(s) of action, combined with evidence that at least some of the haloacetic acids do not share a common mode(s) of action, the lack of a clear trend in carcinogenic potency, the absence of carcinogenic activity of chloroacetic acid in rodents, and the lack of a suitable QSAR model, the current data do not support considering all 13 haloacetic acids as a chemical class.

## 7.3 Potential Haloacetic Acid Subclasses

Although the current data were judged insufficient to support evaluating the set of 13 haloacetic acids as a category, the data were examined to determine if subclasses of haloacetic acids (see Table 7-2) could potentially be evaluated using a category approach. One consideration for this approach is the possibility that different mechanisms might exist for different subclasses of haloacetic acids. Potential analogues within each subclass were also considered to determine if haloacetic acids with cancer data could be matched with a target chemical (without cancer data) to predict the carcinogenicity of that target chemical.

Overall, available data did not identify any subclass (i.e., category based on number or type of halogen substitution) of haloacetic acids that could be evaluated for carcinogenicity because of the lack of a common mode of action, the lack of adequate cancer data, and/or inconsistencies in the cancer data among the members of that subclass. Of the subclasses of haloacetic acids, the confidence for a potential category for using read-across approaches was highest for subclasses that include brominated haloacetic acids, which are more similar with respect to tumor profiles, than those subclasses that included the chlorinated haloacetic acids (i.e., chloroacetic acid, dichloroacetic acid and trichloroacetic acid). The subclass with the highest potential was the di-and trihaloacetic acids which includes three members with animal cancer data (dichloroacetic acid, bromochloroacetic acid, dibromoacetic acid) and three members without animal cancer data (chlorodibromoacetic acid, tribromoacetic acid, bromoiodoacetic acid). A strength of this approach is that chlorodibromoacetic acid and tribromoacetic acid are metabolized to the two dihaloacetic acids with animal cancer data. However, a read-across approach for the other members of a subclass without animal cancer data (bromoidooacetic acid) is more uncertain because of the lack of direct experimental evidence for effects of substitution of bromine or chlorine atoms with iodine on tumorigenicity. Additional toxicological data on key events may contribute to a better understanding of the mode(s) of action and could reduce uncertainty in the read-across of haloacetic acids in the future.

Even though no category could be identified for the 13 haloacetic acids as a class or for subclasses within the set, application of an analogue approach (see Section 7.1.3) is possible for chlorodibromoacetic acid and tribromoacetic acid, which is described in Section 7.4. Potential analogues within each subclass are identified in the Rationale column.

## 7.4 Individual Di- and Tribromohaloacetic Acids

Based on their metabolism to known rodent carcinogens, both bromochloroacetic acid and dibromoacetic acid are predicted to cause cancer in rodents. Chlorodibromo- and tribromoacetic acid are directly metabolized to bromochloro- and dibromoacetic acid, respectively (see Sections 3 and 7.4.1 below) and both dihaloacetic acids, as well as bromodichloroacetic acid (which could also be a potential analogue), have been shown to be rodent carcinogens (see Section 4). Thus, dibromoacetic acid was selected an analogue for read-across to tribromoacetic acid, and bromochloroacetic acid is as an analogue for read-across to chlorodibromoacetic acid based on their metabolism and similar physiochemical properties, toxicokinetics properties, and biological effects in vivo and in vitro (e.g., similar potencies for genetic and oxidative stress) (see Table 7-1). Supporting evidence for these conclusions is discussed below.

### 7.4.1 Metabolism and Toxicokinetics

Trihaloacetic acids are primarily metabolized by reductive dehalogenation that generates a dihaloacetic acid via a free radical intermediate (Anderson et al. 1999; Austin and Bull 1997; Saghir et al. 2011; Xu et al. 1995). Saghir et al. (2011) demonstrated that reductive dehalogenation of tribromoacetic acid in vitro by a rat liver enzyme preparation (microsomes) produced dibromoacetic acid in a 1:1 molar ratio with the bromide ion (Br^−^) liberated and there was no evidence of additional oxidative metabolism. This study also demonstrated that bromodichloro-, chlorodibromo-, and tribromoacetic acids were rapidly metabolized by rat liver microsomes to the di-haloacetic acid product corresponding to the loss of a single Br^−^. Further, substitution of bromines enhanced metabolism, thus, tribromo- and chlorodibromo- are metabolized to their corresponding dihaloacetic acid to a much greater degree than trichloroacetic acid (Saghir et al. 2011; Schultz et al. 1999). (See Section 3 for a more complete discussion of metabolism and toxicokinetics.)

### 7.4.2 Carcinogenicity Data

Near lifetime exposure to bromodichloroacetic acid and dibromoacetic acid in the drinking water caused liver tumors in mice as well as tumors at other tissue sites (listed in Table 7-3) in rats and mice. Thus, chlorodibromoacetic acid and tribromoacetic acid are predicted to be animal carcinogens based on metabolism to bromochloroacetic acid and dibromoacetic acid, respectively. Moreover, all of the di- and trihaloacetic acids tested caused liver tumors in mice, which increases the confidence that chlorodibromoacetic acid and tribromoacetic acid would specifically cause liver tumors in mice. The three tested brominated di-and trihaloacetic acids, (dibromo-, bromochloro- and bromodichloroacetic acids), which are the postulated source chemicals, also caused malignant mesothelioma in male rats. Based on the greater metabolism of the brominated trihaloacetic acids compared to trichloroacetic acid, and the generally greater biological and carcinogenic activity with bromine substitution for chlorine, it is expected that the tumor profiles of chlorodibromoacetic and tribromoacetic acids will be more similar to their direct metabolites (bromochloroacetic acid and dibromoacetic acid, respectively) than the carcinogenicity of trichloroacetic acid and its metabolite dichloroacetic acid. Although no in vivo studies were identified for metabolism of trichloroacetic acid to dichloroacetic acid, oral exposure to trichloroethylene in mice resulted in dichloroacetic acid serum levels of only 0.048% of the trichloroacetic acid serum levels two hours after exposure (Kim et al. 2009) and unlike dichloroacetic acid, trichloroacetic acid administration in a 2-year cancer bioassay did not produce liver tumors in rats (DeAngelo et al. 1996; NTP 1992). The dihalogenated metabolites may not account for all of the carcinogenic potential of the trihaloacetic acids because bromodichloroacetic acid induced more tumor types in rodents than its primary metabolite, dichloroacetic acid.

Table 7-3 Tumor Profiles in Source Chemicals and Predicted Tumor Profiles in Target Chemicals

Endpoint | Source Chemicals | | | Target Chemicals
| BCA (metabolite) | DBA (metabolite) | BDCA | CDBA | TBA
Rats (sex) | Yes | Yes | Yes | Predicted | Predicted
Liver (M/F) | No | No | No | – | –
Mononuclear-cell leukemia (F) | No | Yes | No | – | –
Malignant mesothelioma (M) | Yes | Yes | Yes | Likely site | Likely site
Mammary (F) | Yes | No | Yes | – | –
Skin | No | No | Yes | – | –
Mice (sex) | Yes | Yes | Yes | Predicted | Predicted
Liver (M/F) | Yes | Yes | Yes | Very likely site | Very likely site
Lung (M) | No | Yes | No | – | –
Harderian gland (M) | No | No | Yes | – | –

BCA = bromochloro-, DBA = dibromo-. BDCA = bromodichloro-, CDBA = chlorodibromo-, TBA = tribomoacetic acid, “Likely” or “Very likely” tumor sites are based on metabolism to BCA and DBA, tumor profiles of metabolites or source chemicals and support from mechanistic and other relevant data.

### 7.4.3 Supporting Mechanistic Data

In general, chlorodibromoacetic acid and tribromoacetic acid have similar toxicokinetic and biological effects compared with other brominated haloacetic acids that cause cancer in rodents (Table 7-1 and Table 7-3). Physicochemical properties also show that the electrophilicity increases with bromine content and that the trihaloacetic acids are stronger acids than the dihaloacetic acids. The available data for these two chemicals provide evidence that they also cause oxidative stress and genetic effects, e.g., mutations in bacteria and DNA strand breaks in cultured cells. These events are characteristic of other human carcinogens and support biological plausibility for the carcinogenicity of chlorodibromoacetic and tribromoacetic acids in humans.

### 7.4.4 Conclusions

The set of 13 haloacetic acids considered in this monograph did not form a category to evaluate all of them as a class because of (1) the lack of a well-defined mechanism or mode(s) of action, (2) data that suggest that at least some of the haloacetic acids do not share a common mode(s) of action, (3) the absence of carcinogenicity of chloroacetic acid, and (4) the lack of a clear trend in carcinogenic potency. QSAR model predictions of cancer potency were not consistent with the trends in the key events data. Therefore, the current data are inadequate to support considering all 13 haloacetic acids as a chemical class.

Subclasses of haloacetic acids based on number and types of halogen substitutions were also considered for making read-across predictions of carcinogenicity. The major limitations in the confidence for the read-across analyses are the lack of cancer data for any iodohaloacetic acids or monohaloacetic acids, the negative findings for chloroacetic acid (even though tested at a much lower dose in mice than other haloacetic acids), and data suggesting that trichloroacetic acid may cause cancer by different modes of action than dichloroacetic acid. None of the subclasses of haloacetic acids considered for read-across were considered to have sufficient evidence at this time to support their use as a category.

Consideration of one subclass with six di- and tribrominated haloacetic acids (dibromo-, bromochloro-, bromoiodo-, tribromo-, bromodichloro-, and chlorodibromoacetic acids) led to identification of two individual trihaloacetic acids as target chemicals for read-across based on metabolism and supporting mechanistic data. Cancer predictions were made for two members of this class that did not have cancer data: (1) tribromoacetic acid, which is metabolized to dibromoacetic acid (the source analogue), and (2) chlorodibromoacetic acid, which is metabolized to bromochloroacetic acid (which is the source analogue). Bromodichloroacetic acid is also a rodent carcinogen with similar physicochemical, toxicokinetic, and toxicological properties as the target chemicals, which provides additional support for the conclusion that both tribromoacetic acid and chlorodibromoacetic acid are reasonably anticipated to be rodent carcinogens.