# 6 Mechanistic and Other Relevant Data

Of the 13 haloacetic acids found in drinking water, six were tested for carcinogenicity in a long-term assay in experimental animals (see Section 4). Liver tumors were the most common; however, the brominated haloacetic acids induced tumors at several other sites. As stated in the Methods section, an objective of this monograph is to evaluate whether there are other relevant data that would allow the haloacetic acids to be evaluated as a class. The purpose of this section is to address the following key questions: (1) what are the biologically plausible modes of action through which these compounds may cause cancer in humans; (2) what are molecular initiating events and/or early and late key events associated with the potential modes of action; (3) and do the haloacetic acids, or subclasses, share a common mode(s) of carcinogenic action?

To facilitate the identification of potential mechanisms of cancer, the discussion of the body of literature was generally organized according to the 10 characteristics of carcinogens as defined by Smith et al. (2016) with a few modifications. The outline of this section provides a discussion of the data starting with early events and/or overall experimental support and is as follows: electrophilicity (Section 6.1); alteration of cellular metabolism (Section 6.2, somewhat related to altered nutrient supply, which is part of one of the characteristics of carcinogens); induction of oxidative stress (Section 6.3); genotoxicity and alteration of DNA repair (Section 6.4); induction of epigenetic alterations (Section 6.5); modulation of receptor-mediated effects (Section 6.6); inhibition of GST-ζ (Section 6.7, specific proposed mode of action related to electrophilicity), cell immortalization (Section 6.8); alteration of cell proliferation or cell death (Section 6.9); and induction of chronic inflammation or immunosuppression (Section 6.10). Studies that investigated global gene expression changes are relevant to multiple characteristics of carcinogens and are discussed in Section 6.11. Section 6.12 integrates the mechanistic data and provides a brief synthesis of the findings.

## 6.1 Electrophilicity

Haloacetic acids are recognized as electrophilic compounds due to electron withdrawal from the α-carbon by the halogen substituents, and SN2 reactivity (Pals et al. 2011; Plewa et al. 2010). The available data from screening studies of HAAs for protein and DNA toxicity using complementary sets of E. coli strains (see Table 6-1) indicate that most haloacetic acids have a predominantly soft electrophilic nature and that the likely molecular initiating event is preferential reaction with protein sulfhydryl groups which may result in glutathione depletion-related toxicity. However, three brominated species showed nonspecific reactivity (i.e., reaction with both proteins and DNA) in E. coli strains, and bromoiodoacetic acid was predicted to preferentially cause toxicity-based DNA damage in this screening assay. Reaction with thiol groups on proteins can cause indirect genotoxicity, or impair DNA repair through generation of reactive oxygen species (ROS) (Stalter et al. 2016a). Other modes of action discussed below, including inhibition of pyruvate dehydrogenase kinase (PDK), glyceraldehyde-3-phosphate dehydrogenase (GAPDH), and GST-ζ, are consistent with the soft electrophilic nature of the haloacetic acids. Plewa et al. (2004b) showed that the rank order of cytotoxicity and genotoxicity of the monohaloacetic acids was correlated with their electrophilic reactivity (i.e., iodo- > bromo- ≫ chloroacetic acid). Furthermore, the brominated acetic acids consistently show a greater capacity to induce oxidative stress and a greater mutagenic and genotoxic potency compared to the chlorinated forms (see Sections 6.3 and 6.4). Whether or not this is related to a greater capacity of the brominated di- and trihaloacetic acids to react directly with DNA has not been confirmed.

Table 6-1 Electrophilic Properties of Haloacetic Acids

Haloacetic Acid | E_LUMO_ (eV) | E_LUMO_ (deprotonated) | TR_GSH_^a^ | TR_GSH_^a^ | TR_DNA_ | Classification^b^
Chloroacetic | 4.54 | 9.43 | 0.72 | 0.69 | 0.92 | –
Bromoacetic | 4.47 | 8.68 | 2.30 | 2.05 | 0.84 | GSH
Iodoacetic | 2.88 | 7.18 | 2.68 | 1.61 | 0.81 | GSH
Dichloroacetic | 3.07 | 8.44 | 1.55 | 1.81 | 0.5 | GSH
Dibromoacetic | 2.76 | 7.51 | 1.70 | 1.25 | 1.9 | GSH/DNA
Bromochloroacetic | 3.11 | 7.78 | 2.24 | 1.61 | 3.18 | GSH/DNA
Chloroiodoacetic | 1.54 | 6.40 | 1.39 | 1.31 | 1.17 | GSH
Bromoiodoacetic | 1.60 | 6.46 | 0.59 | 0.64 | 1.47 | DNA
Trichloroacetic | 2.79 | 7.13 | 0.98 | 1.04 | 0.99 | –
Tribromoacetic | 2.42 | 6.12 | 2.39 | 2.13 | 2.61 | GSH/DNA
Bromodichloroacetic | 2.82 | 6.65 | 1.41 | 1.71 | 0.73 | GSH
Chlorodibromoacetic | 2.47 | 6.42 | 1.10 | ^c^ | 0.95 | –

Source: Stalter et al. (2016a). The E. coli assays are used to measure differential cytotoxicity and indicate susceptibility to cytotoxic insults.

E_LUMO_ = energy of the lowest unoccupied molecular orbital. A lower E_LUMO_ suggests a softer electrophile (Schultz et al. 2006). TR_GSH_ = Toxic ratio of EC_50_ of E. coli GSH+/GSH⎼, TR > 1.2 indicates reaction with soft nucleophiles.

TR_DNA_ = Toxic ratio of EC_50_ of E. coli DNA repair +/DNA repair ⎼, TR > 1.2 indicates reaction with hard nucleophiles.

^a^ Values presented for two independent experiments.

^b^ Indicates if compounds react preferentially with proteins (GSH), DNA, nonspecifically with both (GSH/DNA), or neither (⎼).

^c^ Measured only in one experiment with two replicates.

## 6.2 Alteration of Cellular Metabolism

Modes of action that alter cellular energy metabolism include PDK and GAPDH inhibition (Dad et al. 2013; Pals et al. 2011; Pals et al. 2016; Wood et al. 2015). As mentioned above, inhibition of these enzymes is consistent with the soft electrophilic properties of haloacetic acids and results in disruption of cellular energy metabolism and oxidative stress. In the mitochondria, PDKs are a major gatekeeper of pyruvate entry into the tricarboxylic acid cycle while GAPDH is a cytosolic enzyme that catalyzes the sixth step of glycolysis (i.e., conversion of glucose to pyruvate) (Figure 6-1).

Figure 6-1

Inhibition of GAPDH and PDK by Haloacetic Acids and Effects on Glucose Metabolism

In normal differentiated (quiescent) cells, glucose is converted to pyruvate via glycolysis. Under aerobic conditions, most pyruvate enters the mitochondria where it is converted to acetyl-CoA by the pyruvate dehydrogenase (PDH) complex and is used to produce ATP via oxidative phosphorylation. Dichloroacetic acid (DCA) inhibits pyruvate dehydrogenase kinase (PDK), thus, enhancing oxidative metabolism and generation of reactive oxygen species (ROS). Monohaloacetic acids inhibit GAPDH, thus, blocking formation of pyruvate and inducing mitochondrial stress, decreased ATP, and generation of ROS.

Adapted from Bruchelt et al. (2014); Lu et al. (2015); Vander Heiden et al. (2009).

AcCoa = acetyl coenzyme A; ADP = adenosine monophosphate; ATP = adenosine triphosphate; CO_2_ = carbon dioxide; DCA = dichloroacetic acid; GAPDH = glyceraldehyde-3-phosphate dehydrogenase; HAAs = haloacetic acids; O_2_ = oxygen; Oxphos = oxidative phosphorylation; PDH = pyruvate dehydrogenase; PDK = pyruvate dehydrogenase kinase; ROS = reactive oxygen species.

In one study, early life exposure to dichloroacetic acid for 10 weeks increased both the incidence and multiplicity of hepatocellular tumors in male and female mice at 98 weeks of age and was almost as carcinogenic as life-long exposures (see Section 4) (Wood et al. 2015). These authors noted that dichloroacetic acid has been characterized as a metabolic reprogramming agent because it is a structural analogue of pyruvate and inhibits PDK. PDK inhibition results in activation of the pyruvate dehydrogenase complex (PDH), thus, diverting pyruvate metabolism from the glycolytic pathway toward oxidative metabolism. Thus, a plausible mechanism of the latent carcinogenic effects of dichloroacetic acid could involve epigenetic effects leading to persistent changes in cell metabolism and PDH activation. Long-term induction of PDH and other oxidative pathways related to glucose metabolism are of unknown duration, but can promote mitochondrial stress, cell aging, cell injury, DNA damage, and potentially lead to cancer (Wood et al. 2015). Alterations in mitochondrial DNA are common events in hepatocellular carcinoma, and oxidative stress has been proposed to be involved in the progression of hepatocellular carcinoma, although this relationship has not been fully elucidated for haloacetic acids or other liver carcinogens (Hsu et al. 2013).

The monohaloacetic acids inhibit GAPDH in a concentration-dependent manner that is highly correlated with compound reactivity following the rank order of iodo- > bromo- ≫ chloro- (Dad et al. 2013; Hernández-Fonseca et al. 2008; Pals et al. 2011; Pals et al. 2016). GAPDH inhibition blocks glucose metabolism to pyruvate and causes decreased ATP production, mitochondrial stress, increased intracellular Ca^2+^, generation of ROS, and genotoxicity. Dad et al. (2013) also showed that exogenous pyruvate supplementation enhanced ATP production in CHO cells and reduced genomic DNA damage. Treatment with calcium chelators also reduced DNA damage induced in CHO cells by bromoacetic acid (Pals et al. 2016). However, only chloroacetic acid (the weakest GAPDH inhibitor) has been tested for carcinogenicity in a long-term assay, and it was found to not be carcinogenic (NTP 1992).

In recent years, GAPDH has been implicated in other cell functions that are independent of its role in energy metabolism, including DNA repair, cell cycle progression, and cell death (Colell et al. 2009; Zhang et al. 2015a).

## 6.3 Induction of Oxidative Stress

In vitro studies using human or rodent cells and in vivo studies in rodents also show strong evidence that oxidative stress is a common feature of haloacetic acids-induced toxicity and that treatment with antioxidants reduces the genotoxic and cytotoxic effects of haloacetic acids (Celik et al. 2009; Cemeli et al. 2006; Dad et al. 2013; El Arem et al. 2014a; El Arem et al. 2014b; El Arem et al. 2014c; Ondricek et al. 2012; Pals et al. 2011; Stalter et al. 2016a). Numerous studies confirm that all haloacetic acids that have been tested induce oxidative stress either through activating the oxidative stress-responsive nuclear factor E2 related factor/antioxidant response elements (Nrf2/ARE) pathway, lipid peroxidation, and/or inducing oxidative DNA damage (i.e., 8-OHdG adducts) in mammalian cells (Attene-Ramos et al. 2010; Austin et al. 1995; Austin et al. 1996; Celik 2007; Cemeli et al. 2006; Hassoun and Cearfoss 2014; Hassoun et al. 2014; Hassoun and Mettling 2015; Hassoun and Cearfoss 2011; Hassoun et al. 2010a; Hassoun and Dey 2008; Hassoun and Ray 2003; Hassoun et al. 2010b; Larson and Bull 1992; Pals et al. 2013; Pals et al. 2011; Plewa et al. 2010; Procházka et al. 2015; Stalter et al. 2016a; Wang et al. 2014; Zhang et al. 2011).

EPA’s toxicity forecaster (ToxCast) and the National Institutes of Health (NIH) Toxicology in the 21^st^ century (Tox21) databases show that dibromoacetic acid (both ToxCast and Tox21), and tribromoacetic acid and bromochloroacetic acid (Tox21) were positive under the conditions of the assays to screen for an increase in activity of human Nrf2 transcriptional factor (oxidative stress) (https://www.epa.gov/chemical-research/toxicity-forecaster-toxcasttm-data). Bromoacetic acid, chloroacetic acid, bromodichloroacetic acid, dichloroacetic acid, and trichloroacetic acid were negative under conditions of the Tox21 assay. No other haloacetic acids were tested. The Nrf2-ARE signaling pathway is responsive to both electrophilic attack and oxidative stressors (Kensler et al. 2007).

In vitro studies (12 haloacetic acids) in human breast and liver cancer cell lines and in vivo (5 haloacetic acids) studies in rodents that compared biological markers of oxidative stress induced by three or more haloacetic acids reported the same general trends as follows: mono- > di- > trihaloacetic acids and iodinated > brominated ≫ chlorinated acetic acids (Figure 6-2 and Figure 6-3) (Austin et al. 1996; Larson and Bull 1992; Pals et al. 2013; Stalter et al. 2016a). Oxidative stress was measured in vitro by activation of the Nrf2/ARE pathway and in vivo by 8-OHdG and lipid peroxidation. Details on these studies, as well as data from a few other studies, are summarized in Appendix D (Table D-1). Thus, lipid peroxidation and oxidative damage to DNA potentially play a role in the carcinogenicity of haloacetic acids, and the significantly greater levels produced by brominated haloacetic acids suggest a greater potential to induce cancer than the chlorinated forms (Austin et al. 1996). Overall, dichloro- and trichloroacetic acid showed the weakest response.

Figure 6-2

Relative Potency of Haloacetic Acids to Induce Oxidative Stress in Human Cancer Cell Lines; (A) Monohaloacetic Acids, (B) Di- and Trihaloacetic Acids

Source: Stalter et al. (2016a).

AREc32 assay = human breast cancer (MCF7 cell line); ARE-bla assay = human hepatocellular carcinoma (HepG2) cell line; CA = monochloro-; BA = monobromo-; IA = monoiodo-; DCA = dichloro-; DBA = dibromo-; BCA = bromochloro-; CIA = chloroiodo-; BIA = bromoiodo-; TCA = trichloro-; TBA = tribromo-; BDCA = bromodichloro-; CDBA = chlorodibromoacetic acid; AREc32 = activation of Nrf2-ARE oxidative stress response pathway in a human breast cancer cell line MCF7; ARE-bla = activation of oxidative stress response pathway in human hepatocellular carcinoma HepG2 cell line.

Relative potency estimates were derived by dividing all values by the lowest value reported in Table D-1 for the designated endpoint and represent a fold increase over the lowest estimate.

Figure 6-3

Relative Potency of Haloacetic Acids to Induce Oxidative Damage in Mouse Liver In Vivo

Sources: Austin et al. (1996); Larson and Bull (1992).

DCA = dichloro-; DBA = dibromo-; BCA = bromochloro-; TCA = trichloro-; BDCA = bromodichloroacetic acid; TBARS = thiobarbituric acid-reactive substances; 8-OHdG = 8-hydroxydeoxyguanosine.

Relative potency estimates were derived by dividing all values by the lowest value reported in Table D-1 for the designated endpoint and represent a fold increase over the lowest estimate.

## 6.4 Genotoxicity and/or Alteration of DNA Repair

Overall, haloacetic acids have been shown to have some mutagenic activity in bacterial and mammalian cells in vitro and mixed effects regarding DNA and chromosomal damage in vitro in mammalian cells and in vivo in rodents (see Table 6-2). All 13 haloacetic acids have some published genotoxicity data and the mutagenic and genotoxic effects of most of these compounds have been reviewed by U.S. and international agencies (IARC 2013a; 2013b; 2014a; 2014b; NTP 1992; 2007a; 2009; 2015; Richardson et al. 2007; USEPA 2003; 2011a). In addition, the Chemical Effects in Biological Systems (CEBs) database also contains genotoxicity data for 9 haloacetic acids that have been investigated by NTP (https://tools.niehs.nih.gov/cebs3/ui/). The genotoxicity data requested from CEBs is summarized in Appendix D, Table D-2. Dichloro- and trichloroacetic acid are the most extensively studied haloacetic acids, while genotoxicity data for the other compounds are more limited. Section 6.4.1 presents a brief summary of the findings. Studies that compared the mutagenicity/genotoxicity potency of three or more haloacetic acids are considered to be the most informative for evaluating patterns and are reviewed in more detail in Section 6.4.2. Many of these studies were included in the agency reviews.

Table 6-2 Summary of the Mutagenic and Genotoxic Effects of Haloacetic Acids^a^

Test System | Monohaloacetic Acids | | | Dihaloacetic Acids | | | | Trihaloacetic Acids
Test System | CA | BA | IA | | DCA | DBA | BCA | TCA | TBA | BDCA | CDBA
S. typhimurium
TA100 | (±) | + | + | | ± | + | + | – | ±^b,c^ | + | E^d^
TA98 | (±) | nr | nr | | ± | ± | – | – | – | + | –
Other strains | – | nr | nr | | – | ± | – | – | nr | + | nr
E. coli WP2
Reverse mutation | nr | nr | nr | | – | nr | – | nr | nr | + | +
λ Prophage induction | nr | nr | nr | | –^b^ | nr | nr | – | nr | nr | nr
SOS chromotest | – | – | nr | | (+) | + | nr | – | + | nr | nr
Mammalian cells
DNA damage/strand breaks | + | + | + | | – | + | + | – | + | – | (+)
Gene mutation | + | nr | nr | | ± | + | nr | –^d^ | nr | nr | nr
Micronucleus formation | ± | ± | ± | | ± | + | – | ? | nr | – | nr
Chromosomal aberrations | – | nr | + | | + | nr | nr | – | nr | nr | nr
Sister chromatid exchanges | + | nr | nr | | nr | nr | nr | nr | nr | nr | nr
Aneuploidy | nr | nr | nr | | – | nr | nr | nr | nr | nr | nr
Unscheduled DNA synthesis | nr | nr | nr | | nr | + | nr | nr | nr | nr | nr
In vivo
DNA damage/strand breaks | nr | nr | nr | | ± | nr | nr | ± | –^e^ | nr | nr
Gene mutation | –^e^ | nr | –^e^ | | + | nr | nr | nr | nr | nr | nr
Micronucleus formation | –^e^ | –^e^ | nr | | ± | ± | – | ± | –^e^ | – | nr
Chromosomal aberrations | – | nr | nr | | nr | nr | nr | +^f^ | nr | nr | nr

Sources: USEPA (2003; 2011a); IARC (2013a; 2013b; 2014a; 2014b); NTP (1992; 2007a; 2007b; 2009; 2015); Richardson et al. (2007); CEBS (2017); Ali et al. (2014); Kargalioglu et al. (2002); Liviac et al. (2010); Plewa et al. (2004a); Plewa et al. (2010); Stalter et al. (2016a); Teixidó et al. (2015); Varshney et al. (2013; 2014); Zhang et al. (2010).

CA = chloro-; BA = bromo-; IA = iodo-; DCA = dichloro-; DBA = dibromo-; BCA = bromochloro-; TCA = trichloro-; TBA = tribromo-; BDCA = bromodichloroacetic acid; CDBA = chlorodibromoacetic acid; nr = not reported/no data; – = negative, E = equivocal; ± = mixed results; (+) = weak positive; (±) = weak positive or negative; + = positive; ? = reported as positive but results are questionable due to deficiencies in reporting and methods.

^a^ Results are reported without metabolic activation unless otherwise noted.

^b^ Positive with metabolic activation.

^c^ Positive in the fluctuation test (liquid media) with or without metabolic activation.

^d^ Weak positive with metabolic activation in one study.

^e^ Non-mammalian tests: newt larvae (micronucleus), zebrafish (DNA damage), Drosophila (sex-linked recessive lethal mutation).

^f^ Only one oral study in mice, and two i.p. injection studies (mice and chickens).

### 6.4.1 Mutagenic and Genotoxic Effects

The mutagenic and genotoxic effects are summarized in Table 6-2 for 10 haloacetic acids (monochloro-, monobromo-, monoiodo-, dichloro-, dibromo-, bromochloro-, trichloro-, tribromo-, bromodichloro-, and chlorodibromoacetic acid). Chloroiodo-, bromoiodo-, and diiodoacetic acid are not included in this table because the only data available were limited to two studies that evaluated 12 haloacetic acids in the SOS umuC assay or the Comet assay in CHO cells. The results from these two studies are briefly mentioned in this section but are described in more detail in Section 6.4.2.

#### Bacteria

In general, mutagenicity and gentotoxicity (reverse mutations, SOS response, and prophage induction) results in various strains of Salmonella typhimurium and Escherichia coli were mostly negative for trichloroacetic acid; weakly positive or mixed for chloro-, dichloro-, and tribromoacetic acid; and generally positive for bromo-, iodo-, dibromo-, bromochloro-, bromodichloro-, and chlorodibromoacetic acid; metabolic activation was generally not required and did not usually enhance mutagenicity (Table 6-2). Positive results were more frequent when tested with tester strains designed to detect base-pair mutations (e.g., TA100) compared to tester strains detecting frameshift mutations (e.g., TA98). Cemeli et al. (2006) reported that the mutagenicity of iodoacetic acid (identified as the most potent mutagen among the haloacetic acids) was significantly reduced by treatment with antioxidants and supported the hypothesis that haloacetic acids induce genetic damage via an oxidative stress mechanism.

No studies were available for diiodoacetic acid. The only data for chloroiodo- and bromoiodoacetic acid are from a screening study for genetic damage in Salmonella using the SOS umuC assay and both were positive (Stalter et al. 2016a). This study is described in more detail in Section 6.4.2.

#### Genetic Effects in Mammalian Cells In Vitro

In vitro genotoxicity studies were available for all 13 haloacetic acids. The most commonly investigated effects included DNA damage/strand breaks, gene mutations, micronuclei, and chromosomal aberrations while results for sister chromatid exchange, aneuploidy, and unscheduled DNA synthesis were only available for one haloacetic acid. Test systems included CHO cells, mouse lymphoma cells, mouse and rat hepatocytes, human lymphoblastoid cells, and a mouse fibroblast cell line (NIH3T3).

The strongest evidence for genotoxicity is that chloro-, bromo-, iodo-, dibromo-, bromochloro-, tribromo-, and chlorodibromoacetic acids induced DNA strand breaks, with weaker evidence for micronucleus formation (e.g., inconsistent findings across studies depending on the cell type) (Table 6-2). Data also suggest that some of the haloacetic acids may cause chromosomal aberrations and gene mutations albeit fewer chemicals were tested in these assays. Findings for trichloroacetic acid are less clear; however, this chemical is considered not to be genotoxic based on negative in vitro tests and inconsistent results in vivo (IARC 2014b). Although two studies published after the IARC review reported that trichloroacetic acid induced micronuclei and chromosomal aberrations in human peripheral blood lymphocytes, there was no clear dose-response relationship, cytotoxicity issues, and deficiencies in reporting and methodology that made it difficult to interpret the results (Varshney et al. 2013; 2014). Ali et al. (2014) reported that treatment with antioxidants reduced DNA damage induced by the three monohaloacetic acids in human sperm and peripheral blood lymphocytes and micronuclei in human lymphocytes.

Several in vitro studies reported differences in DNA repair kinetics or altered expression of genes involved in DNA repair following exposure to the monohaloacetic acids or trichloroacetic acid (Attene-Ramos et al. 2010; Komaki et al. 2009; Lan et al. 2016; Muellner et al. 2010). Lan et al. (2016) reported that trichloroacetic acid induced strong responses in nucleotide excision repair and mismatch repair and a moderate response in double-strand break repair in a high-throughput toxicogenomic assay. No other haloacetic acid was tested. These results are consistent with oxidative damage to DNA. Komaki et al. (2009) reported that CHO cells treated with bromoacetic acid had a statistically significant slower rate of repair compared to cells treated with chloroacetic acid or iodoacetic acid. The different rates of genomic repair suggest that these compounds induce different DNA lesions and/or a different distribution of DNA lesions. These data are consistent with studies of monohaloacetic acids in nontransformed human cells that reported altered transcription profiles for genes involved in DNA repair, particularly the repair of double-strand DNA breaks (Attene-Ramos et al. 2010; Muellner et al. 2010). Dmitriev and Grodzinsky (1975) reported that blue-green algae (Anacystis nidulans) exposed to iodoacetic acid prior to irradiation had an increased number of single-strand breaks and a lower rate of subsequent DNA repair.

#### Genetic Effects In Vivo

Although limited, the available data indicate that the haloacetic acids are not strong genotoxicants in vivo. The evidence for genotoxicity across haloacetic acids or across different types of endpoints for the same haloacetic acids was largely inconsistent, with some positive findings for DNA or chromosome damage.

In vivo genotoxicity studies were identified for eight haloacetic acids: chloro-, bromo-, dichloro-, dibromo-, bromochloro-, trichloro-, tribromo-, and bromodichloroacetic acid. Endpoints included DNA strand breaks, gene mutation, micronucleus formation, and chromosomal aberrations (Table 6-2). In general, only a few haloacetic acids were tested for each endpoint, and some haloacetic acids were tested for only a few endpoints, thus, limiting the ability to compare genotoxicity potential across haloacetic acids.

Dichloro- and trichloroacetic acid were the only haloacetic acids tested for DNA strand breaks in rodents. Results were mixed in liver but negative in other tissues (IARC 2014a; 2014b). Tribromoacetic acid did not induce DNA damage in zebrafish (Teixidó et al. 2015). Three haloacetic acids were tested for gene mutations with positive findings for dichloroacetic acid (lacI transgenic mouse liver assay), equivocal findings for chloroacetic acid (sex-linked recessive lethal germ cell mutations in Drosophila), and negative findings for iodoacetic acid (sex-linked recessive lethal germ cell mutations in Drosophila (CEBS 2017; IARC 2014a; NTP 1992).

Eight haloacetic acids were tested for micronuclei in rodent or newt larvae, peripheral lymphocytes, or rodent bone marrow. Findings were mixed for dichloroacetic acid (CEBS 2017; IARC 2014a; NTP 2007b), trichloroacetic acid (IARC 2014b), and dibromoacetic acid (IARC 2013a; NTP 2007a) and were negative for bromo-chloroacetic acid (NTP 2015); bromodichloroacetic acid (NTP 2015); and chloro-, bromo-, and tribromoacetic acid (Giller et al. 1997). Chloroacetic acid did not cause chromosomal aberrations in CHO cells but there was some evidence that trichloroacetic can cause chromosome aberrations in bone marrow of mice and chickens when administered by i.p. injection.

#### Mutational Spectra in Liver Tumors

Mouse liver tumors induced by three of the haloacetic acids (dichloro-, trichloro-, and bromodichloroacetic acid) showed different patterns in mutation frequency and/or spectra. A mutational analysis of liver tumors induced by dichloroacetic acid in male mice showed similar incidences of H-ras mutations (~50% to 62%) compared to spontaneous tumors in control animals (~58% to 69%) (Anna et al. 1994; Ferreira-Gonzalez et al. 1995). However, there was a shift in the spectrum of second exon H-ras mutations in dichloroacetic acid-treated animals, where dichloroacetic acid-induced tumors had a significantly lower incidence of CAA → AAA mutations and a significantly higher incidence of CAA → CTA mutations than spontaneous tumors. In contrast, only one H-ras codon 61 mutation was found out of 22 liver tumors (4.5%) examined from female mice exposed to dichloroacetic acid (Schroeder et al. 1997). In trichloroacetic acid-induced mouse liver tumors, both the incidence and mutational spectrum of H-ras mutations (45%) were not significantly different from spontaneous liver tumors, suggesting that trichloroacetic acid promotes the growth of spontaneously initiated hepatocytes (Ferreira-Gonzalez et al. 1995). Although these data suggest that liver tumor induction in male mice by both dichloro- and trichloroacetic acid involves activation of the H-ras proto-oncogene, the specific mechanisms are likely different between the two compounds (Ferreira-Gonzalez et al. 1995; IARC 2014a).

NTP (2015) also conducted a comparative mutation analysis of 30 hepatoblastomas and adjacent hepatocellular carcinomas in mice exposed to bromodichloroacetic acid. The incidence of H-ras mutations in bromodichloroacetic acid-induced hepatocellular carcinomas (13%) was about the same as observed in adjacent hepatoblastomas (7%) but was lower than in spontaneous hepatocellular carcinomas (55%). On the other hand, the incidence of Ctnnb1 (ß-catenin) mutations in treatment-related hepatocellular carcinomas (10%) was lower than in adjacent hepatoblastomas (23%) but higher than in spontaneous tumors (2%). There were no data for historical spontaneous hepatoblastomas in mice. H-ras codon 61 and Ctnnb1 exons 2 and 3 mutation spectra were different for the two tumor types, and although the sample size is small, the data suggest that these tumors are distinct entities. Only two hepatoblastomas had H-ras mutations (both CAA → CTA) while three of four H-ras mutations in hepatocellular carcinomas contained CAA → CGA mutations and the other was a CAA → CTA mutation. There were no clear mutation spectrum patterns in the seven hepatoblastomas or the three hepatocellular carcinomas that contained Ctnnb1 mutations.

### 6.4.2 Mutagenic and Genotoxic Potency

Mutagenic or genotoxic potency and cytotoxicity of three or more haloacetic acids were directly compared in several studies in bacteria (S. typhimurium strain TA100, SOS umuC assay) and mammalian cells (HGPRT mutations, Comet and p53-bla assays) (Kargalioglu et al. 2002; Plewa et al. 2010; Plewa et al. 2004b; Richardson et al. 2008; Stalter et al. 2016a; Zhang et al. 2010; Zhang et al. 2016). These data are shown in Appendix D (Table D-3 and Table D-4) and are reported as the fold increase relative to the least potent haloacetic acid in each of five in vitro genetox assays in the figures below. Data for the umuC assay are plotted separately because the general trends present in the other assays are not as apparent in the umuC assay (discussed below). The SOS umuC assay is a screening test and does not provide a direct measurement of DNA damage or mutagenesis but rather measures the activation of SOS umuC-dependent error prone DNA repair. Data for a few other studies shown in Appendix D, Table D-3 and Table D-4 (Attene-Ramos et al. 2010; Escobar-Hoyos et al. 2013; Giller et al. 1997; Ono et al. 1991; Procházka et al. 2015) are not included in the figures below but show the same general patterns.

The data show that the mutagenic/genotoxic potency is highly influenced by both the number and type of halogen atoms with the general rank order of potency as: mono- > di- > trihaloacetic acids and iodinated > brominated ≫ chlorinated acetic acids and is consistent with that reported for oxidative stress in the previous section. In fact, all haloacetic acids that were active toward DNA in bacteria or mammalian cells also induced oxidative stress (Stalter et al. 2016a).

Notable exceptions to the general trends reported above included the lack of mutagenic activity for the monohalogenated acetic acids and the high potency of brominated trihaloacetic acids, particularly tribromoacetic acid, in the SOS umuC assay (see Appendix D, Table D-3) (Stalter et al. 2016a). Stalter et al. (2016a) noted that induction ratios in the umuC assay were excluded from the data analysis when cytotoxicity exceeded 50%, so the lack of mutagenic activity by monohaloacetic acids in the umuC assay may be a result of cytotoxicity masking induction of the reporter gene. However, Zhang et al. (2016) showed that the monohaloacetic acids were active in the SOS umuC assay. Therefore, Figure 6-4 integrates data for umuC for the di- and trihaloacetic acids from Stalter et al. (2016a) with data for the monohaloacetic acids from Zhang et al. (2016). Although no explanation was given for the high potency of the brominated trihaloacetic acids (especially tribromoacetic acid) in the umuC assay (Stalter et al. 2016a), the trihaloacetic acids were negative or weakly positive in other bacterial systems and in mammalian cells. Tribromoacetic acid is not included in Figure 6-4 because it exhibited a 2,500-fold increase relative to chloro- and trichloroacetic acid and appears to be an outlier.

Figure 6-4

Relative Genotoxicity Potency Estimates of Haloacetic Acids in the SOS-umuC Assay

Sources: Stalter et al. (2016a); Zhang et al. (2016).

CA= monochloro-; BA = monobromo-; IA = monoiodo-; DCA = dichloro-; DBA = dibromo-; BCA = bromochloro-; CIA = chloroiodo-; BIA = bromoiodo-; TCA = trichloro-; BDCA = bromodichloro-; CDBA = chlorodibromoacetic acid.

Relative potency estimates were derived by dividing all values by the lowest value reported in Table D-3 for the designated endpoint and represent a fold increase over the lowest estimate. Data for the monohaloacetic acids, DCA, and TCA were derived from Zhang et al. (2016) and were estimated from a figure at an induction ratio of 1.5 using WebPlot Digitizer (https://arohatgi.info/WebPlotDigitizer/app/). Tribromoacetic acid value >2,500 omitted due to scale.

Exceptions to the general trends observed in the in vitro genetox studies summarized in Figure 6-5 (Ames TA100 strain, HGPRT mutations, p53-bla, and Comet) include slightly more DNA damage in CHO cells exposed to dibromoacetic acid compared to bromoiodo- or diiodoacetic acid (Plewa et al. 2010), and dibromoacetic acid induced an 8-fold higher HGPRT mutant frequency in CHO cells than bromoacetic acid (Zhang et al. 2010).

Figure 6-5

Relative Genotoxicity Potency Estimates of Haloacetic Acids in Bacteria and Mammalian Cells

Sources: Kargalioglu et al. (2002); Plewa et al. (2010); Plewa et al. (2004b); Stalter et al. (2016a); Zhang et al. (2010).

CA= monochloro-; BA = monobromo-; IA = monoiodo-; DCA = dichloro-; DBA = dibromo-; DIA = diiodo-; BCA = bromochloro-; CIA = chloroiodo-; BIA = bromoiodo-; TCA = trichloro-; TBA = tribromo-; BDCA = bromodichloro-; CDBA = chlorodibromoacetic acid.

Relative potency estimates were derived by dividing all values by the lowest value reported in Table D-3 and Table D-4 for the designated endpoint and represent a fold increase over the lowest estimate. Value of zero indicates that the compound was tested but inactive. (A) Monohaloacetic acid), (B) Di- and trihaloacetic acids.

## 6.5 Induction of Epigenetic Alterations

Three haloacetic acids (dichloro-, dibromo-, and trichloroacetic acid) induced hypomethylation of DNA and the promoter regions of oncogenes (c-myc and insulin-like growth factor 2 [IGF-II]) genes in rodents. Hypomethylation of the promoter regions leads to increased expression of these

genes and may represent early events in the hepatocarcinogenicity of these haloacetic acids (IARC 2013a; 2014a; 2014b; Tao et al. 2005; Tao et al. 2004a). In contrast, the global methylation pattern in liver tumor and nontumor DNA harvested from mice after 98 weeks following early-life exposure to dichloroacetic acid was not altered (Wood et al. 2015). DNA methylation status has been suggested as a possible screening tool for predicting the potential carcinogenicity of the haloacetic acids (Kuppusamy et al. 2015; Pereira et al. 2001; Tao et al. 2004b). However, no clear potency trends were observed. Findings for the three compounds are summarized across studies below and the data from the individual studies are reported in Appendix D, Table D-5.

Dose-dependent hypomethylation of DNA from normal liver tissue, liver tumor, and normal kidney tissue; hypomethylation in the promoter regions of IGF-II, c-jun, and c-myc genes; and increased mRNA expression of these genes were reported in mice exposed to dichloro-, dibromo-, or trichloroacetic acid (Pereira et al. 2001; Pereira et al. 2004a; Tao et al. 2004b; Tao et al. 2005; Tao et al. 2004a; Tao et al. 2000a; 2000b; Tao et al. 1998). Dibromoacetic acid also induced liver and kidney DNA hypomethylation in male rats (Tao et al. 2005; Tao et al. 2004a). Hypomethylation patterns varied depending on the exposure conditions and type of tissue (tumor vs. nontumor).

Several studies show that hypomethylation was correlated with the carcinogenic and tumor-promoting activity of both dichloro- and trichloroacetic acid in the liver and kidney of rodents but that the mechanisms of their carcinogenic activity may be different (Pereira et al. 2001; Pereira et al. 2004a; Tao et al. 2004b; Tao et al. 2005; Tao et al. 2000b; Tao et al. 1998). Dichloro- and trichloroacetic acid-induced hypomethylation of the promoter region of the c-myc gene in mouse liver coincided with enhanced cell proliferation and suggests that these compounds induce hypomethylation by inducing DNA replication and inhibiting methylation of the newly synthesized DNA (Ge et al. 2001). When co-administered with chloroform, both trichloroacetic acid and dichloroacetic acid induced hypomethylation and promoted kidney tumors in male (but not female) mice (Pereira et al. 2001). Hypomethylation induced by haloacetic acids was also prevented by prior treatment with methionine, suggesting that haloacetic acids deplete S-adenosyl methionine levels (Pereira et al. 2004b; Pereira et al. 2004a; Tao et al. 2005; Tao et al. 2000a; 2000b).

## 6.6 Modulation of Receptor-mediated Effects

Overall, the data suggest that the carcinogenic activity of trichloroacetic acid in mouse liver is consistent with peroxisome proliferation (IARC 2004b; 2014b). The lack of a carcinogenic response in rats exposed to trichloroacetic acid may be explained by a much lower extent of peroxisome proliferation compared to mice (DeAngelo et al. 1989). In contrast, rats were more sensitive to the hepatocarcinogenicity of dichloroacetic acid than mice (DeAngelo et al. 1996).

Peroxisome proliferation, as measured by palmitoyl-CoA oxidation, appears to be a common effect of the seven haloacetic acids tested in vitro but with wide variation in potency and efficacy in cultured rat hepatocytes (Appendix D, Figure D-1) (Walgren et al. 2004). The lowest effective concentrations, based on palmitoyl-CoA oxidation, varied over about two orders of magnitude. Within the monohalo-substituted series, iodoacetic acid was more potent than bromo- or chloroacetic acid; however, no clear patterns were observed for the different halogen substitutions for the di- or trihaloacetic acid series. While monobromo- and monoiodoacetic acid induced significant increases in palmitoyl-CoA oxidation at the lowest concentrations (50 to 100 µM), higher concentrations were cytotoxic. Thus, the cytotoxicity of the monohaloacetic acids would likely limit their effectiveness as PPARα activators in vivo. Overall, dibromoacetic acid was the most effective inducer of palmitoyl-CoA reaching 6.2-fold at the maximum concentration tested (3 mM). Dichloro-, trichloro-, and tribromoacetic acids were modest inducers of palmitoyl CoA with much flatter concentration/response curves. However, these data are not consistent with the available in vivo data discussed below.

In vitro studies using human cells also reported variable results. Peroxisome proliferation (as measured by palmitoyl-CoA oxidation) was not detected in one study using human cell lines exposed to dichloro- or trichloroacetic acid; however, palmitoyl-CoA oxidation was not detected in control human hepatocytes in these studies (Walgren et al. 2000a; 2000b). Other in vitro studies have shown that human PPARα is activated by both dichloro- and trichloroacetic acid (IARC 2014b). Trichloroacetic acid at concentrations >1 mM induced comparable dose-related transactivation in human and mouse PPARα in vitro (Maloney and Waxman 1999).

In vivo studies in rats and/or mice exposed to brominated or chlorinated haloacetic acids in drinking water showed a dose-related increase in acyl-CoA oxidase activity or hepatic peroxisome proliferation for dibromo- and trichloroacetic acid and the positive control (clofibric acid) but not for other haloacetic acids tested (chloro-, dichloro-, bromochloro-, or bromodichloroacetic acid) (DeAngelo et al. 1989; NTP 2015; Parrish et al. 1996; Tao et al. 2004a; Xu et al. 1995). Dichloroacetic acid produced a small, but significant increase only at the high dose while the response to dibromoacetic acid was dose related up to 1 g/L but then declined at 3 g/L (Parrish et al. 1996).

Trichloroacetic acid and dichloroacetic acid are relatively weak PPARα agonists requiring mM concentrations (Corton 2008; DeAngelo et al. 1996; DeAngelo et al. 2008; DeAngelo et al. 1999; Laughter et al. 2004). However, dose-response characteristics for dichloroacetic acid show that PPARα is not activated at concentrations that induce liver tumors in either rats or mice and indicates that the mode of action of dichloroacetic acid is PPARα-independent (DeAngelo et al. 1996; DeAngelo et al. 1999). In contrast, dose-response characteristics for trichloroacetic acid show that there is a relatively good correlation between trichloroacetic acid-induced liver tumors and induction of markers of PPARα activation in the mouse (DeAngelo et al. 2008). In addition, markers of PPARα activation are elevated at trichloroacetic acid doses that are below or coincident with doses that induce mouse liver tumors, and trichloroacetic acid-induced mouse liver tumors have properties similar to those induced by classic peroxisome proliferators (Corton 2008; DeAngelo et al. 2008).

## 6.7 Inhibition of GST-ζ

GST-ζ inhibition has been suggested as a specific mode of action relevant to dihaloacetic acid-induced liver cancer in rodents; however, the available data are insufficient to fully define the key events or to assess their necessity or sufficiency for carcinogenicity. Several polymorphic variants of GST-ζ have been identified that differ in their susceptibility to inactivation (Blackburn et al. 2001; Blackburn et al. 2000; Board and Anders 2011; Cantor et al. 2010; Fang et al. 2006; Hayes and Strange 2000; Li et al. 2012; Shroads et al. 2010; Tzeng et al. 2000). Inhibition of GST-ζ by successive or continuous doses of dihaloacetic acids reduces metabolism and prolongs the plasma half-life (Gonzalez-Leon et al. 1999; Schultz et al. 2002).

GST-ζ, also known as maleylacetoacetate isomerase (MAAI), catalyzes the penultimate step in the tyrosine catabolism pathway and metabolizes maleylacetoacetate to fumarylacetoacetate and maleylacetone to fumarylacetone (Anderson et al. 2004; Board and Anders 2011; Cornett et al. 1999; Schultz et al. 2002; Stacpoole 2011; Stacpoole et al. 2008; Theodoratos et al. 2009). These reactive metabolites may accumulate following inhibition of GST-ζ, react with macromolecules, and induce oxidative stress (Blackburn et al. 2006). Hereditary tyrosinemia type 1 is a metabolic disease caused by a deficiency of the enzyme involved in the last step of tyrosine catabolism. Individuals with this disease develop hepatocellular carcinoma at a young age (Stacpoole 2011; Tanguay et al. 1996).

Schultz et al. (2002) reported that dichloroacetic acid reduced MAAI activity over 80% in young mice but not in old mice suggesting that reduced MAAI activity is unlikely to be the sole carcinogenic mode of action for dichloroacetic acid and may be important only during the early stages of exposure. This conclusion is further supported by observations that GST-ζ-deficient mice do not spontaneously develop hepatocellular carcinoma (Fernández-Cañón et al. 2002; Schultz et al. 2002).

## 6.8 Cell Immortalization

Iodo- and dibromoacetic acid (the only haloacetic acids tested) caused cell transformation in an immortalized aneuploid mouse cell line (NIH3T3 or Balb/c 3T3 cells) (Fang and Zhu 2001; Wei et al. 2013). This assay is responsive to the later stages in carcinogenic transformation (i.e., induction of morphologically transformed foci (Tanaka et al. 2012). Moreover, Wei et al. (2013) reported that iodoacetic acid-transformed cells also exhibited anchorage-independent growth, agglutination with concanavalin A, and they formed aggressive fibrosarcomas when injected into Balb/c nude mice. Cell transformation assays are capable of detecting both genotoxic and non-genotoxic carcinogens and validation studies have shown generally good concordance with rodent bioassay results and reproducibility (Corvi et al. 2012; Creton et al. 2012; Tanaka et al. 2012).

## 6.9 Alteration of Cell Proliferation and Cell Death

Some data suggest that dichloro- and trichloroacetic acid alter cell proliferation and apoptosis; however, the data are inconsistent and the effects appear to be transitory [reviewed in (IARC 2014a; 2014b; USEPA 2003; 2011a)]. Several studies reported hepatocyte proliferation, increased thymidine incorporation in hepatic DNA, and increased cell division rates in trichloroacetic acid-induced hepatic foci and tumors (Channel et al. 1998; DeAngelo et al. 2008; Dees and Travis 1994; Ge et al. 2001; IARC 2014b; Pereira 1996; Stauber and Bull 1997; Styles et al. 1991). Increased labeling of hepatic DNA was observed at sub-necrotic doses suggesting that cell proliferation was not due to regenerative hyperplasia (Dees and Travis 1994). Studies with dichloroacetic acid reported increased cell proliferation of c-jun-positive hepatocytes, reparative hyperplasia in the liver, increased numbers of hepatic foci and hyperplastic nodules, increased cell replication rates in altered foci, promotion of growth and survival of initiated cells, and a dose-related decrease in apoptosis (IARC 2014a; Richmond et al. 1991; Sanchez and Bull 1990; Snyder et al. 1995; Stauber and Bull 1997; Stauber et al. 1998). Other studies have suggested that dichloro- and trichloroacetic acids are not direct-acting mitogens; however, dichloroacetic acid inhibited apoptosis and synergistically enhanced the mitogenic response to epidermal growth factor (EGF) in cultured rat hepatocytes (DeAngelo et al. 1991; Walgren et al. 2005).

Increased cell proliferation has been associated with increased expression of IGF-II as this gene has both mitogenic and anti-apoptotic activity in the liver (Tao et al. 2004b). As mentioned above (Section 6.5), both trichloro- and dichloroacetic acids increased c-myc and IGF-II expression and enhanced cell proliferation in rodent liver (Ge et al. 2001; Tao et al. 2004b; Tao et al. 2004a). Stauber et al. (1998) reported that both dichloro- and trichloroacetic acid promoted the formation of anchorage-independent mouse hepatocytes in vivo and in vitro in a dose-dependent manner. The phenotypes of the anchorage-independent colonies promoted by dichloroacetic acid were primarily c-jun positive while those promoted by trichloroacetic acid were mainly c-jun negative, consistent with the phenotypes from liver tumors induced by these compounds. These data suggest that the mode of action of dichloro- and trichloroacetic acid may be to selectively stimulate the clonal expansion of phenotypically different populations of initiated cells.

Some in vitro data suggest that trichloroacetic acid and dichloroacetic acid, but not iodoacetic acid, inhibit gap-junctional intercellular communication (Benane et al. 1996; Klaunig et al. 1989; Si et al. 1987). Loss of gap junctional cellular communication may be an important step in carcinogenesis (Aasen et al. 2016). No data were available for other haloacetic acids regarding effects on gap-junctional intercellular communication. Benane et al. (1996) reported a dose- and treatment time-related inhibitory response for both haloacetic acids in a normal liver epithelial cell line from male Sprague Dawley rats. The lowest concentration and shortest time to reduce gap-junctional intracellular communication, as measured by dye transfer, was 1 mM over 1 hour for trichloroacetic acid compared to 10 mM over 6 hours for dichloroacetic acid. Thus, trichloroacetic acid appeared to be more potent than dichloroacetic acid. Trichloroacetic acid significantly reduced dye transfer in mouse hepatocytes at 0.1 mM to 1 mM after 4 hours treatment but not after 8 hours or 24 hours (Klaunig et al. 1989). In contrast, dye transfer was not affected in rat hepatocytes exposed to trichloroacetic acid concentrations up to 1 mM for as long as 24 hours.

## 6.10 Induction of Chronic Inflammation or Immunosuppression

The evidence that haloacetic acids induce chronic inflammation or immunosuppression is generally weak and inconsistent and neither process has been identified as a potential mode of action for dichloro-, trichloro-, bromochloro-, or dibromoacetic acid (IARC 2013a; 2013b; 2014a; 2014b). Nevertheless, some data regarding these effects were available for the chloro-, bromo-, iodo-, dichloro-, dibromo-, bromochloro-, trichloro-, and bromodichloroacetic acids and are briefly reviewed here.

In the two-year cancer bioassay studies, mild chronic inflammation in the liver was reported in male mice chronically exposed to trichloroacetic acid (DeAngelo et al. 2008) or dichloroacetic acid (Daniel et al. 1992) but not in rats or mice exposed to dibromo-, bromochloro-, or chlorodibromoacetic acid (NTP 2007a; 2009; 2015). None of the 12 haloacetic acids evaluated activated the NF- KB stress-response pathway for inflammation in vitro using the human THP-1 leukemia cell line (Stalter et al. 2016a). However, Pals et al. (2013) reported that the three monohaloacetic acids, at non-cytotoxic concentrations, upregulated cyclooxygenase-2 (COX-2) in nontransformed human intestinal epithelial cells (line FHs 74 Int), suggesting a possible inflammatory response. Bromo- and iodoacetic acids also modulated the MAPK pathway in FHs 74 Int cells which suggests a response to cell stress and inflammation (Attene-Ramos et al. 2010).

Few studies have investigated the effects of haloacetic acids on the immune system. Neither dichloro- nor trichloroacetic acid were immunotoxic in rats exposed to concentrations of up to 5 g/L in drinking water for 90 days (Mather et al. 1990). Ohashi et al. (2013) reported that dichloroacetic acid improved immune function and increased antitumor immunotherapeutic activity. Dibromoacetic acid did not significantly affect humoral immunity or innate immune function in mice at concentrations up to 1 g/L in drinking water for 28 days (Smith et al. 2010a). Other studies have suggested that monoiodo-, dichloro-, dibromo-, or trichloroacetic acid induce some immune responses, including increased serum IgG and IgM in autoimmune-prone MRL^+/+^ mice, histological changes in the thymus and spleen, increased immune cell apoptosis, T cell activation and increased cytokine expression, and suppressed in vitro immune functions (Cai et al. 2007; Gao et al. 2008; Gao et al. 2016; Pan et al. 2015; Si et al. 1987).

## 6.11 Effects on Gene Expression

Toxicogenomics studies were available for chloro-, bromo-, iodo-, dichloro-, bromochloro-, trichloro-, and bromodichloroacetic acids and are discussed separately for the monohaloacetic acids and the di- and trihaloacetic acids. These data show that the haloacetic acids induce gene expression changes relevant to several of the characteristics of carcinogens and possible modes of action discussed in this monograph.

Comparative human cell toxicogenomic analysis indicated that the monohaloacetic acids altered the transcription levels of genes involved in stress response to DNA damage and regulation of different stages in cell cycle progression or apoptosis and provide support for several of the proposed modes of action (Attene-Ramos et al. 2010; Muellner et al. 2010; Pals et al. 2013). The major cell pathways affected are shown in Table 6-3. Most of these pathways show a strong association with carcinogenesis (Khanna and Jackson 2001; Plewa and Wagner 2015).

Table 6-3 Transcriptome Pathways in Human Cells Induced by Monohaloacetic Acids

Pathway | Chloro- | Bromo- | Iodo-
ATM signaling | + | + | +
Cell cycle control | + | + | NA
Cyclins and cell cycle regulation | + | NA | NA
MAPK signaling | NA | + | +
p53 signaling | NA | + | +
BRCA1, BRCA2, and ATR mediated cancer susceptibility and dsDNA repair | + | + | +
Nrf2/ARE-dependent ROS | + | + | +
PTGS2 (COX2)-mediated | + | + | +
MPO, LPO and NOX5 ROS | + | + | +
GSH/GSR | + | + | +
Peroxiredoxin oxidative stress | + | + | NA

Source: Plewa and Wagner (2015).

NA = pathway not affected.

Several gene expression studies show that the di- and trihaloacetic acids induce expression changes in genes involved in oxidative stress-responsive pathways, DNA damage and repair, cell cycle progression, cell proliferation, metabolism, cancer progression, and apoptosis. However, the data are insufficient to determine any clear patterns in gene expression profiles that are related to physiochemical or toxicological properties of the haloacetic acids. These studies compared gene expression changes in normal liver tissue, preneoplastic liver nodules, and liver tumors from mice exposed to dichloro-, trichloro-, or bromodichloroacetic acid and control mice; mouse sperm or rat mesotheliomas exposed to bromochloroacetic acid; normal mammary gland tissue and tumors in rats exposed to bromodichloroacetic acid; and yeast treated with trichloroacetic acid and the data are summarized in Appendix D, Table D-6) (Choi and Park 1996; Kim et al. 2006; Lan et al. 2016; NTP 2015; Nelson et al. 1990; Thai et al. 2001; 2003; Tully et al. 2005).

Mice exposed to dichloroacetic acid for 4 weeks showed similar gene expression profiles in liver tissue as observed in dichloroacetic acid-induced liver tumors (Thai et al. 2001; 2003). Trichloroacetic acid-activated pathways involved in oxidative DNA damage and tumor progression (Lan et al. 2016; Nelson et al. 1990) while bromochloroacetic acid altered expression of genes involved in cell communication and adhesion, cell cycle and cell proliferation, metabolism, signal transduction, apoptosis, invasion, and metastasis (Kim et al. 2006; Tully et al. 2005). Distinct gene expression profiles were observed across four different tissues following bromodichloroacetic acid exposure: hepatocellular carcinomas, hepatoblastomas, and adjacent normal liver tissue from exposed rats as well as normal liver tissue from controls (NTP 2015). Gene expression changes in treatment-related nontumor liver tissue were consistent with neoplastic signaling and may suggest that microenvironment changes preceded neoplastic transformation due to chemical treatment. However, these gene expression changes may also have been influenced by the microenvironment of the adjacent hepatocellular carcinomas. The gene expression profiles of mouse hepatoblastomas were similar to early embryonic mouse livers, suggesting that these tumors arose from the transformation of a hepatic stem or multipotent progenitor cell, while hepatocellular carcinomas arose from transformed hepatocytes. Significant upregulation of eight genes was found in mammary gland tumors from rats exposed to bromodichloroacetic acid but were not found in spontaneous tumors; five of these genes were associated with TGF-beta signaling and an aggressive tumor phenotype (Harvey et al. 2016; NTP 2015).

## 6.12 Mode of Action Integration and Synthesis

Overall, the data suggest that the haloacetic acids may induce cancer through electrophilic reactions with macromolecules leading to altered gene expression, inhibited protein function, oxidative stress, and mutagenic and genotoxic effects. The data suggest that the mechanisms are complex and likely involve multiple interactions of toxicokinetic factors and modes of action, as well as unknown factors and modes of action that may differ somewhat among the various subclasses of haloacetic acids based on halogen substitution patterns.

The potential modes of action and key events associated with the characteristics of carcinogens are listed in Table 6-4. Most compounds have been associated with most of the 10 characteristics of carcinogens and potential modes of action, with the possible exception of PPAR-alpha activation, are relevant to human cancer. Figure 6-6 identifies the specific haloacetic acids and subclasses that have been linked to a particular mode of action through in vitro and/or in vivo testing. The identification of the potential modes of action of the haloacetic acids is limited because not all 13 haloacetic acids have been tested for all of the key events. Biologically plausible modes of action with moderate to strong experimental support include oxidative damage, epigenetic alterations (i.e., DNA hypomethylation) leading to gene expression changes, GAPDH and PDK inhibition leading to metabolic reprogramming and oxidative stress, disruption of tyrosine catabolism by dihaloacetic acids via inhibition of GST-ζ, and PPARα activation. These effects are further supported by transcriptomic analyses showing that haloacetic acids affect expression of genes involved in oxidative stress response, DNA damage and repair, cell growth and proliferation, tissue remodeling, apoptosis, angiogenesis, cancer progression, fatty acid metabolism, and xenobiotic metabolism. Direct genotoxicity does not appear to be a primary mode of action for the haloacetic acids and, overall, the data suggest that oxidative stress is responsible for the mutagenic and genotoxic effects of these compounds.

Table 6-4 Possible Modes of Carcinogenic Action for Haloacetic Acids and the 10 Characteristics of Carcinogens

Characteristic(s) of Carcinogens | Mode of Action | Key Events
Electrophilicity | Irreversible binding to macromolecules | 1. Haloacetic acids have an electrophilic structure that can react with peptides, proteins, or DNA to form adducts. 2. Protein or DNA adducts result in altered activity or DNA damage that advances acquisition of multiple critical traits contributing to carcinogenesis.
Altered nutrient supply, electrophilicity, induction of oxidative stress | Reprogramming cellular energy metabolism (inhibition of pyruvate dehydrogenase kinase (PDK) | 1. Haloacetic acids inhibition of PDK increases pyruvate dehydrogenase complex activity and oxidative metabolism. 2. Increase in oxidative metabolism leads to an increase in reactive oxygen species (ROS) and oxidative stress. 3. Oxidative stress leads to acquisition of multiple, critical traits contributing to carcinogenesis.
Altered nutrient supply, electrophilicity, induction of oxidative stress | Inhibition of glyceraldehyde-3-phosphate dehydrogenase (GAPDH) | 1. Haloacetic acids inhibition of GAPDH leads to inhibition of glycolysis. 2. Inhibition of glycolysis leads to reduced ATP levels and repressed pyruvate generation. 3. Reduced pyruvate leads to mitochondrial stress, ROS generation, cytotoxicity, and DNA damage.
Induction of oxidative stress | Oxidative stress | 1. Haloacetic acids induce oxidative stress through multiple pathways. 2. Oxidative stress can cause mutations and damage to proteins, lipids, and DNA. 3. Mutations and damage to macromolecules activate cell-signaling pathways, induce genomic instability, and cell transformation and lead to cancer.
Genotoxicity and/or alteration of DNA repair | Mutagenicity and genotoxicity | 1. Haloacetic acids induce genetic damage in critical genes or form pro-mutagenic adducts. 2. Insufficient or mismatch repair of genetic damage leads to fixed genetic damage. 3. Unrepaired genetic damage leads to clonal expansion of initiated cells. 4. Clonal expansion leads to tumor formation.
Induction of epigenetic alterations | DNA hypomethylation | 1. Haloacetic acids induce epigenetic changes (particularly DNA hypomethylation) that alter gene expression, DNA repair, and cell phenotype. 2. These changes advance acquisition of multiple critical traits contributing to carcinogenesis.
Electrophilicity, induction of oxidative stress | Glutathione S-transferase zeta (GST-ζ) inhibition | 1. Haloacetic acids bind to GST-ζ causing irreversible inhibition. 2. Deficiency in GST-ζ results in reduced metabolism and clearance of dihaloacetic acids, higher levels of tyrosine metabolites, oxidative stress, and activation of stress-response pathways. 3. Accumulation of tyrosine metabolites and oxidative stress lead to tumor formation.
Modulation of receptor mediated effects | Peroxisome proliferator-activated receptor α (PPARα) activation | 1. Haloacetic acids activate PPARα in the liver. 2. PPARα activation leads to altered cell proliferation and apoptosis. 3. Alterations in cell proliferation and apoptosis cause clonal expansion of initiated cells. 4. Clonal expansion of initiated cells leads to tumor formation.
Cell immortalization, induction of epigenetic alterations, genotoxicity | Cell transformation | 1. Haloacetic acids induce genetic and/or epigenetic alterations in the target cell. 2. These changes lead to altered gene expression and signal transduction and acquisition of a malignant phenotype including blocked cellular differentiation and morphological transformation, acquisition of an unlimited life span, genetic instability, anchorage-independent growth, foci formation, clonal expansion, and tumor formation.
Alteration of cell proliferation or cell death | Sustained cellular proliferation and suppression of apoptosis | 1. Haloacetic acids induce sustained cell proliferation, cytotoxicity and reparative hyperplasia, and/or decreased programmed cell death (apoptosis) in target tissues. 2. Increased cell proliferation and reduced apoptosis. 3. Increases the probability that initiated cells will form and survive. 4. Survival of initiated cells leads to clonal expansion, foci formation, and tumor formation.

Sources: Dad et al. (2013); USEPA (2011b); IARC (2013a; 2013b; 2014a; 2014b); Pals et al. (2011); Smith et al. (2016); Wood et al. (2015).

Figure 6-6

Interactions of Potential Modes of Action and Key Events Associated with Haloacetic Acid-induced Carcinogenicity

MOA = mode of action; MIE = molecular initiating event; HAA = haloacetic acid; PPARα = peroxisome proliferator-activated receptor alpha; GAPDH = glyceraldehyde-3-phosphate dehydrogenase; PDK = pyruvate dehydrogenase kinase; GST-ζ = glutathione S-transferase zeta; ? = uncertain.