# 5 Human Cancer Studies

Water disinfection by-products include a complex mixture of chemicals created from reactions between water disinfection agents (such as chlorine) and organic matter in the water. These include a wide variety of compounds that lack reliable exposure measurement methods. Often, trihalomethanes as a class or a specific trihalomethane are used as a proxy measure for the complex mixture of chemicals in disinfected water (see Section 2.7.2 and Figure 2-5). To date, only one human epidemiological study has been identified that evaluated haloacetic acid exposures (i.e., any of the 13 individual chemicals or as a class or subclass) in humans and cancer risk. However, in addition to this cohort study, existing data in the primary literature of exposures to water disinfection mixtures or specific classes of water disinfection by-products (such as trihalomethanes) may serve as surrogates for chlorinated water. Findings from the cohort study are discussed below, along with a brief discussion of human cancer findings and any potential association with disinfection by-products. The discussion summarizes the review in the general remarks section of the International Agency for Research on Cancer (IARC) monograph on Some Chemicals Present in Industrial and Consumer Products, Food and Drinking-Water (IARC 2013c) and updates the literature since that monograph.

## 5.1 Cohort Study

Jones et al. (2017) investigated the risk of kidney cancers from ingested nitrate and other disinfection by-products in the Iowa Women’s Health Study (IWHS), a cohort of 41,836 post-menopausal women followed for up to 24 years, from 1986 to 2010. This study categorized women’s drinking water exposure by source: public water, private well, and other sources. Exposure then to water disinfection products was split into time at that source (≤10 years or >10 years), and the cancer analysis was done on women exposed to public water sources for greater than 10 years (N = 15,577). Exposure to haloacetic acids, including a mixture of five regulated haloacetic acids (monochloroacetic acid, monobromoacetic acid, dichloroacetic acid, dibromoacetic acid, trichloroacetic acid) and individual haloacetic acids (dichloroacetic acid, trichloroacetic acid, and bromochloroacetic acid, which is unregulated) and trihalomethanes (total as well as individual) were estimated via an expert assessment that used available measures (data from plants, water source, quality, treatment, and disinfection type). A total of 266 incident kidney cancers were observed among all women in the study, with 125 occurring among women with greater than 10 years exposure to a public water source. No associations were seen between kidney cancer risk and either individual or combined haloacetic acid or trihalomethane measures. The data for this study are presented in Table 5-1.

Table 5-1 Haloacetic Acid Exposure and Kidney Cancer

Reference, Study Design, Location, and Year | Population Description & Exposure Assessment Method | Exposure Category or Level | Exposed Cases/Deaths | Hazard Ratio (95% CI) | Co-variates Controlled | Comments, Strengths, and Weaknesses
Jones et al. (2017) Cohort Study – The Iowa Women’s Health Study USA 19862010 | Women age 55–69 at baseline exposed to public water source for greater than 10 years. Total population N = 41,836 Women exposed to public water source >10 years: N = 15,577 | HAA5* (μg/L) <1.89 1.89–3.48 3.49–6.43 >6.43 P trend Continuous Years >30 μg/L HAA5^+^ 0 <16 ≥16 P trend Continuous Dichloroacetic acid (μg/L) <1.65 1.65–2.27 2.28–4.84 >4.84 P trend Continuous Trichloroacetic acid (μg/L) <0.25 0.25–0.63 0.64–1.69 >1.69 P trend Continuous Bromochloroacetic acid (μg/L) <0.1 0.1–0.94 0.95–1.89 >1.89 P trend Continuous | 38 27 35 25 125 109 8 8 125 36 35 28 26 46 7 46 26 52 18 28 27 | Ref. 1.0 0.84 (0.51–1.4) 0.78 (0.49–1.2) 0.65 (0.39–1.1) 0.18 0.99 (0.98–1.0) Ref 1.0 0.76 (0.37–1.6) 0.74 (0.36–1.5) 0.32 0.99 (0.95–1.0) Ref 1.0 0.99 (0.62–1.58) 0.79 (0.48–1.30) 0.75 (0.45–1.24) 0.30 0.98 (0.95–1.01 Ref 1.0 0.40 (0.18–0.89) 0.89 (0.58–1.36) 0.68 (0.42–1.10 0.26 0.99 (0.96–1.01) Ref 1.0 1.20 (0.69–2.08) 0.76 (0.47–1.26) 0.78 (0.49–1.25) 0.25 0.95 (0.86–1.05) | Age, smoking status, pack-years of smoking, body mass index, ln-transformed NO_3_-N | Exposure duration: Participants included in this analysis were exposed for at least 10 years at the same location. Confounding: While difficult to separate the effects of the individual disinfection by-products, this study attempts to control for some of these factors in the analysis, along with other related factors. Strengths: Long exposure duration for participants and low loss to follow-up. The study attempted to estimate exposure levels in a systematic way for participants. Weaknesses: Lack of regular measurement at all water facilities, and lack of individual measurement for exposure, and inability to fully separate the effects of the individual disinfection by-products. Study enrollment restricted to premenopausal women.

* HAA5: regulated haloacetic acids (monochloroacetic, dichloroacetic, trichloroacetic, monobromoacetic, and dibromoacetic acids).

^+^ Number of years the annual average level was >½ the MCL (maximum containment level) value.

## 5.2 Other Human Cancer Studies of Disinfection By-products

The IARC working groups reviewed several epidemiological studies (both cohort and case-control studies) of chlorinated water or specific disinfection by-products (i.e., trihalomethanes as a class or chloroform) primarily on urinary bladder cancer and some other types of cancer but did not make a formal evaluation of potential cancer hazards from chlorinated water because the monographs were on individual disinfection by-products. In general, IARC (2013c) reported positive associations in all nine case-control studies of DBP or chlorinated water, or both, and urinary bladder cancer, including a dose-response relationship in some studies. Among these studies, five found an association between the highest exposure levels of chlorinated water and bladder cancer (three among all participants, one among men only and one for women only). Six studies found an association between trihalomethanes and bladder cancer, with five finding a dose-response relationship (three of these for men only). One study (Cantor et al. 2010) found the association varied by genetic polymorphisms in GST and CYP genes. Results from three cohort studies were inconsistent, with only one study reporting a statistically significant risk to women for exposure to chloroform; however, no dose response was seen.

Increased risk for other types of cancer was seen in a limited number of studies, with two cohort studies reporting increased risks for lung, melanoma, breast, and esophageal cancers. Increased risks for kidney, brain, melanoma, and non-melanoma skin cancers were reported in four individual case-control studies. However, IARC (2004a; 2004b; 2013a; 2013b) has not made a formal evaluation of specific disinfection by-products, as the studies were not specific for the individual disinfection by-products under review. This complexity of exposure to a mixture and the correlation between different types of disinfection by-products make human epidemiological studies of individual chemicals difficult to conduct and interpret.

Since the IARC reviews, one case-control study in Spain was identified that found an elevated odds ratio (OR = 1.43, 95% CI = 0.83 to 2.46) for colorectal cancer and the highest level of brominated trihalomethanes (compared to lowest level), but did not find an association with total trihalomethanes (Villanueva et al. 2017). Another analysis within the Iowa Women’s Health Study also found a non-significant increase in bladder cancer for those with the highest level of nitrate-nitrogen and trihalomethane exposure (Jones et al. 2016). Based on the evidence to date, there appears to be some association with disinfection by-products and cancer, particularly with urinary bladder cancer, but the extent of the involvement of the haloacetic acids individually or as a class is unclear.

## 5.3 Preliminary Level of Evidence Conclusion

Overall, the data from cancer studies in humans are inadequate to evaluate the relationship between human cancer and exposure specifically to the individual haloacetic acids, subclasses of haloacetic acid, or haloacetic acids as a class.