# 4 Studies of Cancer in Experimental Animals

This section reviews and assesses the evidence from carcinogenicity studies in experimental animals exposed to any of the 13 haloacetic acids examined in this monograph. Experimental animal carcinogenicity studies were identified using methods described in the protocol (NTP 2017). A total of 24 publications were identified that reported on exposure of experimental animals to a haloacetic acid and met the following inclusion criteria: (1) reported on the presence or absence of neoplastic and related preneoplastic lesions, (2) had a concurrent or historical control group, and (3) either had an observational duration of 12 months or greater for rats and mice or were co-carcinogen exposure studies (initiation-promotion and other co-carcinogen studies). Three papers were excluded because they duplicated the data in other peer-reviewed reports (Carter et al. 2003; Kissling et al. 2009; Melnick et al. 2007). Two additional papers were not peer reviewed and were not included; however, data from one report (Bull 1989) was also reported in a later, peer-reviewed publication, which was considered. The other report by Innes and Ulland (1968) was not considered useful enough to justify peer reviewing it for inclusion.

Section 4.1 provides an overview of the studies, Section 4.2 assesses the quality of the studies, Section 4.3 reports the findings of the studies, organized by the type of neoplasms observed, and Section 4.4 provides a synthesis of the results from all studies.

## 4.1 Overview of the Studies

The 19 remaining publications reported a total of 40 studies; 32 were carcinogenicity studies, three were in transgenic animals (NTP 2007b), and five were initiation-promotion studies (Gwynn and Salaman 1953; Herren-Freund et al. 1987; Pereira et al. 1997). These studies exposed rodents to seven of the 13 haloacetic acids considered in this monograph; six of which were tested in long-term carcinogenicity studies: monochloroacetic acid (DeAngelo et al. 1997; NTP 1992), dichloroacetic acid (Bull et al. 1990; Daniel et al. 1992; DeAngelo et al. 1996; DeAngelo et al. 1991; DeAngelo et al. 1999; Richmond et al. 1995; Wood et al. 2015), dibromoacetic acid (NTP 2007a), bromochloroacetic acid (NTP 2009), trichloroacetic acid (Bull et al. 1990; DeAngelo et al. 1997; DeAngelo et al. 2008; Herren-Freund et al. 1987; Pereira 1996; Von Tungeln et al. 2002), and bromodichloroacetic acid (NTP 2015). In addition, five initiation-promotion studies were identified for monoiodoacetic acid (Gwynn and Salaman 1953), dichloroacetic acid (Herren-Freund et al. 1987; Pereira et al. 1997), and trichloroacetic acid. All haloacetic acids were tested at multiple doses up to at least 1,000 mg/L for all six tested in long-term studies and up to 5,000 mg/L for dichloroacetic acid and trichloroacetic acid.

An overview of these studies is provided below (Table 4-1), and tables describing the study conditions and tumor findings are included in Appendix C, Table C-56 through Table C-59. Exposure in almost all of these studies was by an oral route, mostly in drinking water, although two studies were by gavage (NTP 1992), and one study used intraperitoneal exposure (Von Tungeln et al. 2002). Another study exposed a transgenic animal model, Tg.AC hemizygous mice, by dermal application (NTP 2007b).

Table 4-1 Overview of Cancer Studies in Experimental Animals

Species, Strain, (Sex) | Route | Exposure/Study Durations | Reference
Monochloroacetic acid
Rat F344/N (M&F) | Gavage | 104 wk/104 wk | NTP (1992)
Mouse B6C3F_1_ (M&F) | Gavage | 104 wk/104 wk | NTP (1992)
Rat, F344/M, (M) | Drinking water | 104 wk/104 wk | DeAngelo et al. (1997)
Monoiodoacetic acid
Mouse albino “S” strain (NR) | Dermal | 27 wk/30 wk | Gwynn and Salaman (1953) ^a^
Dichloroacetic acid
Rat F344 (M) | Drinking water | 100 wk/100 wk & 103 wk/103 wk | DeAngelo et al. (1996)
Rat F344 (M) | Drinking water | 60 wk/60 wk (interim sacrifice) & 104 wk/104 wk | Richmond et al. (1995)
Mouse B6C3F_1_ (M) | Drinking water | 60–75 wk/60–75 wk | DeAngelo et al. (1991)
Mouse B6C3F_1_ (M) | Drinking water | 90–100 wk/90–100 wk | DeAngelo et al. (1999)
Mouse B6C3F_1_ (M) | Drinking water | 61 wk/61 wk | Herren-Freund et al. (1987)
Mouse B6C3F_1_ (M) | Drinking water | 61 wk/61 wk | Herren-Freund et al. (1987) ^a^
Mouse B6C3F_1_ (M&F) | Drinking water | 10 wk/94 wk | Wood et al. (2015)
Mouse B6C3F_1_ (F) | Drinking water | 360 d/576 d & 360 d/360 d | Pereira (1996)
Mouse B6C3F_1_ (F) | Drinking water | 44 wk/50 wk | Pereira et al. (1997) ^a^
Mouse B6C3F_1_ (M) | Drinking water | 52 wk/52 wk | Bull et al. (1990)
Mouse B6C3F_1_ (M) | Drinking water | 104 wk/104 wk | Daniel et al. (1992)
Mouse FVB Tg.AC (M&F) | Drinking water | 26 wk/41 wk & 26 wk/26 wk | NTP (2007b) ^b^
Mouse p53 haploinsufficient (M&F) | Drinking water | 26 wk/41 wk & 26 wk/26 wk | NTP (2007b) ^b^
Mouse FVB Tg.AC (M&F) | Dermal | 39 wk/39 wk & 26 wk/26 wk | NTP (2007b) ^b^
Dibromoacetic acid
Rat F344/N (M&F) | Drinking water | 106 wk/106 wk | NTP (2007a)
Mouse B6C3F_1_ (M&F) | Drinking water | 106 wk/106 wk | NTP (2007a)
Bromochloroacetic acid
Rat F344/N (M&F) | Drinking water | 105 wk/105 wk | NTP (2009)
Mouse B6CC3F_1_ (M&F) | Drinking water | 105 wk/105 wk | NTP (2009)
Trichloroacetic acid
Rat F344/N (M) | Drinking water | 104 wk/104 wk | DeAngelo et al. (1997)
Mouse B6C3F_1_ (M) | Drinking water | 60 wk/60 wk & 104 wk/104 wk | DeAngelo et al. (2008)
Mouse B6C3F_1_ (M) | Drinking water | 61 wk/61 wk | Herren-Freund et al. (1987)
Mouse B6C3F_1_ (M) | Drinking water | 61 wk/61 wk | Herren-Freund et al. (1987) ^a^
Mouse B6C3F_1_ (F) | Drinking water | 576 d/576 d & 360 d/360 d | Pereira (1996)
Mouse B6C3F_1_ (F) | Drinking water | 44 wk/50 wk | Pereira et al. (1997) ^a^
Mouse B6C3F_1_ (M) | Drinking water | 52 wk/52 wk | Bull et al. (1990)
Mouse B6C3F_1_ (M&F) | IP inj. | 15 d/20 mo & 15 d/12 mo | Von Tungeln et al. (2002)
Bromodichloroacetic acid
Rat F344/NTac (M&F) | Drinking water | 104–105 wk/104–105 wk | NTP (2015)
Mouse B6C3F_1_ (M&F) | Drinking water | 105 wk/105 wk | NTP (2015)

^a^ Initiation-promotion study.

^b^ Transgenic animal model.

## 4.2 Study Quality Assessment

Each of these primary studies was systematically evaluated by two independent reviewers for its ability to inform the cancer hazard evaluation using a series of signaling questions related to the following study performance elements: study design, exposure conditions, outcome, confounding, reporting and analysis, and overall utility (see RoC Handbook (https://ntp.niehs.nih.gov/go/rochandbook)). A summary of the studies’ quality assessments is provided below (Table 4-2), and details of each study assessment and quality criteria on a study-by-study basis are reported in Appendix C.

Table 4-2 Quality Evaluations of Cancer Studies in Experimental Animals

Study | Study Design | | | | | Exposure Conditions | | | Outcome | | Confounding | Reporting and Analysis | Overall Utility
Study | Randomization | Control | Animal Model* | Statistical Power* | Purity | Dosing | Exposure Duration* | Dose Level* | Pathology Methods | Equal Treatment | Confounding | Statistical Analysis
Monochloroacetic acid
NTP (1992), Mouse M/F | +++ | +++ | +++ | +++ | +++ | ++[underlined: +]^a^ | +++ | ++[underlined: +]^a^ | +++ | +++ | ++^b^ | +++ | +++
NTP (1992), Rat M/F | +++ | +++ | ++ | +++ | +++ | ++ | +++ | ++ | +++ | +++ | +++ | +++ | ++
DeAngelo et al. (1997), Rat M | NR | +++ | ++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++
Monoiodoacetic acid
Gwynn and Salaman (1953),^c^ Mouse NR | NR | +++ | + | + | NR | +++ | ++ | + | + | NR | + | NR | +
Dichloroacetic acid
DeAngelo et al. (1996), Rat M (100 wk), 2 doses | NR | +++ | ++ | ++ | +++ | +++ | +++ | ++ | ++ | ++ | ++ | +++ | ++
DeAngelo et al. (1996), Rat M (103 wk), 1 dose | NR | +++ | ++ | ++ | +++ | +++ | +++ | + | ++ | ++ | ++ | +++ | ++
Richmond et al. (1995), Rat M (104 wk) | +++ | +++ | ++ | ++ | NR | +++ | +++ | +++ | ++ | ++ | + | ++ | ++
DeAngelo et al. (1991), Mouse M (60/75 wk) 3 doses | +++ | +++ | ++ | ++ | +++ | +++ | +++ | +++ | ++ | ++ | ++ | +++ | +++
DeAngelo et al. (1991), Mouse M (60 wk), 1 dose | +++ | +++ | ++ | + | +++ | +++ | +++ | + | ++ | +++ | ++ | +++ | ++
DeAngelo et al. (1999), Mouse M, 4 doses | +++ | +++ | ++ | ++ | +++ | +++ | +++ | +++ | ++ | ++ | ++ | +++ | ++
Herren-Freund et al. (1987), Mouse M | NR | +++ | ++ | ++ | +++ | +++ | +++ | + | ++ | +++ | +++ | +++ | ++
Herren-Freund et al. (1987),^c^ Mouse M | NR | +++ | ++ | ++ | +++ | +++ | +++ | + | ++ | +++ | +++ | +++ | ++
Wood et al. (2015), Mouse M | NR | +++ | +++ | ++ | ++ | +++ | ++ | +++ | + | +++ | ++ | +++ | ++
Wood et al. (2015), Mouse F | NR | +++ | +++ | ++ | ++ | +++ | ++ | ++ | + | +++ | ++ | +++ | ++
Pereira (1996), Mouse F (360 d) | +++ | +++ | ++ | ++ | NR | +++ | +++ | +++ | ++ | +++ | ++ | +++ | ++
Pereira (1996), Mouse F (576 d) | +++ | +++ | ++ | ++ | NR | +++ | ++ | +++ | ++ | +++ | ++ | +++ | ++
Pereira et al. (1997),^c^ Mouse F | +++ | +++ | ++ | ++ | + | +++ | +++ | +++ | ++ | +++ | ++ | ++ | +
Bull et al. (1990), Mouse M | +++ | +++ | ++ | + | ++ | +++ | +++ | ++ | + | + | + | + | +
Daniel et al. (1992), Mouse M | +++ | +++ | ++ | ++ | +++ | +++ | +++ | + | + | ++ | ++ | +++ | ++
NTP (2007b),^d^ Mouse M/F FVB Tg.AC dermal (39 wk), 3 doses | +++ | +++ | + | + | +++ | ++ | +++ | +++ | +++ | +++ | +++ | +++ | +
NTP (2007b),^d^ Mouse M/F FVB Tg.AC dermal (26 wk), 3 doses | +++ | +++ | + | ++ | +++ | ++ | ++ | +++ | +++ | +++ | +++ | +++ | +
NTP (2007b),^d^ Mouse M FVB Tg.AC (41 wk), 3 doses | +++ | +++ | + | + | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +
NTP (2007b),^d^ Mouse F FVB Tg.AC (41 wk), 3 doses | +++ | +++ | + | + | +++ | ++ | +++ | +++ | +++ | +++ | +++ | +++ | +
NTP (2007b),^d^ Mouse M FVB Tg.AC (26 wk), 3 doses | +++ | +++ | + | ++ | +++ | + | ++ | +++ | +++ | +++ | +++ | +++ | +
NTP (2007b),^d^ Mouse F FVB Tg.AC (26 wk), 3 doses | +++ | +++ | + | ++ | +++^a^ | +^e^ | ++ | +++ | +++ | +++ | +++ | +++ | +
NTP (2007b),^d^ Mouse M/F p53 haploinsufficient (41 wk), 3 doses | +++ | +++ | + | + | +++ | ++ | +++ | +++ | +++ | +++ | +++ | +++ | +
NTP (2007b),^d^ Mouse M/F p53 haploinsufficient (26 wk), 3 doses | +++ | +++ | + | ++ | +++ | ++ | ++ | +++ | +++ | +++ | +++ | +++ | +
Dibromoacetic acid
NTP (2007a) Mouse M/F | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | ++ | +++ | +++
NTP (2007a) Rat M/F | +++ | +++ | +++ | +++ | +++ | ++[underlined: +]^a^ | +++ | +++ | +++ | +++ | ++ | +++ | +++
Bromochloroacetic acid
NTP (2009) Rat M/F | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++
NTP (2009) Mouse M/F | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++
Trichloroacetic acid
DeAngelo et al. (1997) Rat M | NR | +++ | ++ | +++ | +++ | ++[underlined: +]^a^ | +++ | +++ | +++ | +++ | +++ | +++ | +++
DeAngelo et al. (2008) Mouse M (60 wk) | +++ | +++ | +++ | +++ | +++ | +++ | ++ | +++ | +++ | ++ | +++ | +++ | +++
DeAngelo et al. (2008) Mouse M (104 wk), 1 dose | +++ | +++ | +++ | +++ | +++ | +++ | +++ | + | +++ | +++ | +++ | +++ | ++
DeAngelo et al. (2008) Mouse M (104 wk), 2 doses | +++ | +++ | +++ | +++ | +++ | ++ | +++ | ++ | +++ | +++ | +++ | +++ | ++
Herren-Freund et al. (1987) Mouse M | NR | +++ | ++ | ++ | +++ | ++[underlined: +]^a^ | +++ | +++ | +[underlined: +]^a^ | +++ | +++ | +++ | ++
Herren-Freund et al. (1987)^c^ Mouse M | NR | +++ | ++ | ++ | +++ | ++[underlined: +]^a^ | +++ | +^b^ | +[underlined: +]^a^ | +++ | +++ | +++ | ++
Pereira (1996) Mouse F (576 d) | +++ | +++ | ++ | ++ | NR | +++ | +++ | +++ | ++ | +++ | ++ | +++ | ++
Pereira (1996) Mouse F (360 d) | +++ | +++ | ++ | ++ | NR | +++ | ++ | +++ | ++ | +++ | ++ | +++ | ++
Pereira et al. (1997)^c^ Mouse F | +++ | +++ | ++ | ++ | NR | +++ | +++ | +++ | ++ | +++ | ++ | ++ | +
Bull et al. (1990) Mouse M | +++ | +++ | ++ | + | ++ | +++ | +++ | ++ | + | + | + | + | +
Von Tungeln et al. (2002) Mouse M/F (20 mo) | + | +++ | ++ | ++ | NR | + | + | ++ | ++ | ++ | ++ | +++ | ++
Von Tungeln et al. (2002) Mouse M/F (12 mo) | + | +++ | ++[underlined: +]^a^ | ++ | NR | + | + | ++ | ++ | ++ | ++ | +++ | ++
Bromodichloroacetic acid
NTP (2015), Rat M/F | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++
NTP (2015), Mouse M/F | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++

* These factors contribute to the sensitivity of the study.

^a^ ERRATUM: Errors were identified in the Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. The number of + signs in these cells was incorrect in the original table. These errors have been corrected; one + sign was added and underlined.

^b^ ERRATUM: Errors were identified in the Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. The number of + signs in these cells was incorrect in the original table. These errors have been corrected; one + sign was removed.

^c^ Initiation/promotion study.

^d^ Transgenic animal model.

^e^ ERRATUM: Errors were identified in the Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. The number of + signs in these cells was incorrect in the original table. These errors have been corrected; two + signs were removed.

Most studies conducted by NTP (1992; 2007a; 2007b; 2009; 2015) and some of the studies conducted by DeAngelo (1997; 2008) were considered the most informative because they used a sufficient number of experimental animals for a near lifetime exposure duration, tested three dose levels [except for NTP (1992), which used two dose levels] along with an untreated control, and performed full necropsies with histopathology. None of the studies used step-sectioning technique to evaluate an organ. The rat NTP (1992) study had a moderate level of utility because the rats were very sensitive to monochloroacetic acid in the 13-week study and developed non-carcinogenic toxicity, which required the dose level to be reduced in the 2-year study. DeAngelo et al. (1997) and the NTP studies also included historical control data. Data on historical controls is useful for identifying rare tumors.

Many studies were considered somewhat less informative (moderate overall utility) primarily because of sensitivity issues (e.g., elements that limited their ability to detect a true effect, or evaluate dose-response effects) but would not be expected to cause false positives in the studies. The studies with overall rating of ++ either had fewer animals (Daniel et al. 1992; DeAngelo et al. 1996; DeAngelo et al. 1991; DeAngelo et al. 1999; Herren-Freund et al. 1987; Richmond et al. 1995; Von Tungeln et al. 2002; Wood et al. 2015), used only one sex of animal (Daniel et al. 1992; DeAngelo et al. 1996; DeAngelo et al. 1991; DeAngelo et al. 1999; Herren-Freund et al. 1987; Pereira 1996; Richmond et al. 1995), had a shorter exposure duration (Pereira 1996; Von Tungeln et al. 2002; Wood et al. 2015), had to decrease study duration due to hindleg paralysis (Richmond et al. 1995), tested only one dose level (Daniel et al. 1992; DeAngelo et al. 1996; DeAngelo et al. 1991; Herren-Freund et al. 1987), or did not perform full necropsies (Daniel et al. 1992; DeAngelo et al. 1996; DeAngelo et al. 1991; DeAngelo et al. 1999; Herren-Freund et al. 1987; Pereira 1996; Richmond et al. 1995; Wood et al. 2015).

Only a few studies were considered to be of low quality (overall utility of +) because of not reporting chemical purity (Pereira et al. 1997), testing at only a single dose level (Gwynn and Salaman 1953), use of a small number of animals (Bull et al. 1990; Gwynn and Salaman 1953), or the lack of full necropsies and instead focusing on specific target organs (Bull et al. 1990; Gwynn and Salaman 1953; Pereira et al. 1997) [in one study only a sample of randomly picked gross liver lesions were examined histologically (Bull et al. 1990) and in one study, lesions were classified based on “macroscopic” examination (Gwynn and Salaman 1953)].

Other studies rated as low utility were not conventional carcinogenicity studies and instead were initiation-promotion studies that did not include groups that exposed animals to the haloacetic acid promoter without the initiator (Gwynn and Salaman 1953; Pereira et al. 1997) or they used p53 haploinsufficient or Tg.AC hemizygous transgenic mice. The p53 haploinsufficient transgenic mice may not be able to detect non-genotoxic carcinogens (Gulezian et al. 2000; Spalding et al. 2000; Tennant and Spalding 1996). Concerns for the Tg.AC hemizygous mice include production of false positive results from vehicle controls (Jacobs and Hatfield 2013), or minor skin abrasions (Fuhrman et al. 2005), and its inability to distinguish between promotion and de novo carcinogenicity (Jacobs and Hatfield 2013; Luijten et al. 2016). The use of the Tg.AC hemizygous mouse is no longer recommended by the FDA (Luijten et al. 2016). Another limitation of these studies was the small number of animals used for each treatment group, further limiting the ability to detect small changes in incidence.

## 4.3 Neoplastic Findings from Carcinogenesis Studies

Results are summarized below for tumors induced by seven mono-, di-, and trihaloacetic acids (monochloroacetic acid, monoiodoacetic acid, dichloroacetic acid, dibromoacetic acid, bromochloroacetic acid, trichloroacetic acid, and bromodichloroacetic acid). Section 4.3.1 discusses liver neoplasms, which are reported by themselves because they developed in mice in all positive studies. The other sections discuss other tumor sites (Section 4.3.2), studies with transgenic animals (Section 4.3.3), and initiation-promotion studies (Section 4.3.4). Table 4-4 in Section 4.4 summarizes results by individual haloacetic acid. The following text summarizes neoplastic findings across tumor sites and across haloacetic acids rather than providing a detailed study-by-study description. Information on the individual cancer studies can be found in tabular form in Appendix C.

Table 4-4 Results from Cancer Studies in Experimental Animals^a^

Chemical (Route) | Neoplasms in Mice (Sex) | Neoplasms in Rats (Sex) | Reference
Monochloroacetic acid
Gavage | None | Not tested | NTP (1992) ^b^
Dichloroacetic acid
Drinking water | NF | Liver – hepatocellular carcinoma (M) Liver – hepatocellular adenoma or carcinoma (M) | DeAngelo et al. (1996) ^b^
Drinking water | Liver – hepatocellular adenoma and carcinoma (M/F) | NF | DeAngelo et al. (1991; 1999),^b^ Herren-Freund et al. (1987), Daniel et al. (1992),^b^ Wood et al. (2015), Pereira (1996)
Dibromoacetic acid
Drinking water | Liver – hepatocellular adenoma and carcinoma (M/F) Liver – hepatoblastoma (M) Lung – alveolar/bronchiolar adenoma (M) Lung – alveolar/bronchiolar adenoma or carcinoma (M) | Malignant mesothelioma (M) Mononuclear-cell leukemia (F) | NTP (2007a) ^b^
Bromochloroacetic acid
Drinking water | Liver – hepatocellular adenoma and carcinoma (M/F) Liver – hepatoblastoma (M) | Malignant mesothelioma (M) Mammary gland – fibroadenoma (multiple only) (F) Large intestine – adenoma (rare) (M/F) | NTP (2009) ^b^
Trichloroacetic acid
Drinking water | Liver – hepatocellular adenoma and carcinoma (M/F) | NF | DeAngelo et al. (2008) ^b^ Herren-Freund et al. (1987) Pereira (1996)
Bromodichloroacetic acid
Drinking water | Liver – hepatocellular adenoma (F) Liver – hepatocellular carcinoma (M/F) Liver – hepatoblastoma (M/F) Harderian gland – adenoma (M) Harderian gland – adenoma or carcinoma (combined) (M) | Malignant mesothelioma (M) Mammary gland – fibroadenoma and carcinoma (F) Skin – fibroma (M) Skin – keratoacanthoma (M) Skin – squamous-cell papilloma, keratoacanthoma, sebaceous gland adenoma, basal-cell adenoma, basal-cell carcinoma, or squamous-cell carcinoma (combined) (M) | NTP (2015) ^b^

F = female; M = male; NF = none found.

^a^ The percent tumor incidences for all neoplasms listed were significantly increased over control values except for adenoma of the large intestine in rats (M/F) which was considered treatment-related due to the rarity of these tumors and progression to malignancy.

^b^ Full necropsy was performed.

### 4.3.1 Liver

Overall, the data from studies that exposed rodents to haloacetic acids provide strong evidence that di- and trihaloacetic acids cause liver neoplasms in rodents (see Table C-56 in Appendix C). Liver neoplasms were significantly induced by all dihaloacetic acids (dichloroacetic acid, dibromoacetic acid, bromochloroacetic acid) and trihaloacetic acids, (trichloroacetic acid, bromodichloroacetic acid) tested by exposure to male and female mice in the drinking water in well-conducted studies for at least 12 months. Significant increases in liver neoplasms for male rats were reported for dichloroacetic acid only.

The routes of exposure were primarily through drinking water with one study using intraperitoneal injection. Either route would be expected to result in initial exposure of the liver by uptake from the gastrointestinal tract circulation via the hepatic portal system. Exposure of the liver to the relatively high concentration of haloacetic acid prior to metabolism and distribution to other tissues could be a factor in the common occurrence of liver neoplasms.

All chronic cancer studies in this section are of moderate study quality except for Bull et al. (1990) which has a lower study quality rating (see Appendix C). Some studies focused on the liver pathology only and did not do a full necropsy on the whole animal; limitations on study quality would not apply to histopathology results for this tissue.

Details on liver findings for the individual HAAs are discussed first, followed by a discussion of the findings across studies.

#### Chlorine-only Haloacetic Acids

No liver tumors were induced by the only monohaloacetic acid tested, monochloroacetic acid, which was administered by gavage to rats and mice (NTP 1992) and in drinking water to rats (DeAngelo et al. 1997).

Dichloroacetic acid was tested for carcinogenicity in more studies than any other haloacetic acid, with 11 publications reporting 13 drinking water studies that varied by species (rat or mouse), sex, dose levels tested (from 50 mg/L up to 5,000 mg/L), and duration of exposure and observation (from 10 weeks to 104 weeks for chronic studies). These studies did not generally provide explanations for the choices of duration, or dose used. In general, most of the studies were in male mice only, a stop-exposure study was reported for male and female mice, two studies were in female mice only, and two studies were in male rats only (see Table 4-1). Overall, increased incidences of liver tumors were reported for both sexes in mice and male rats over a range of doses and duration of exposure indicating a robust tumorigenic response for dichloroacetic acid.

In male mice, dichloroacetic acid induced a significant increase in hepatocellular adenoma and carcinoma at 5,000 mg/L for 60 weeks in a multiple-dose study for 60 to 75 weeks (50, 500, 5,000 mg/L) (DeAngelo et al. 1991) and at lower doses (starting at 1,000 mg/L) in a multi-dose, two-year study (0, 500, 1,000, 2,000, 3,500 mg/L, see Figure 4-1A) (DeAngelo et al. 1999). Three single high-dose studies of dichloroacetic acid in male mice yielded significant incidence rates for hepatocellular adenoma and carcinoma at 500 mg/L in a two-year study (Daniel et al. 1992) and 3,500 mg/L (DeAngelo et al. 1991) or 5,000 mg/L (Herren-Freund et al. 1987) in 60-week studies. Bull et al. (1990) reported that 50% (5 of 10) of male mice treated with 2,000 mg/L of dichloroacetic acid in the drinking water for one year developed hepatocellular carcinoma; however, only mice with gross liver lesions were histologically examined, including only two out of the 35 control mice in this study, which also had other study limitations (see Appendix C). In female mice, dichloroacetic acid caused significant increases in the incidence of hepatocellular adenoma at the mid (860 mg/L) and high dose (2,600 mg/L) and carcinoma at the high dose (2,600 mg/L) in an ~1.5 year study (Pereira 1996) (see Figure 4-1D); only hepatocellular adenoma was significantly increased at the high dose in a one-year study reported in the same publication.

Figure 4-1

Hepatocellular Carcinoma in Female and Male Mice Exposed to Di- and Trihaloacetic Acids

Sources: NTP (2007a; 2009; 2015), for bromine-containing HAA in male (A) and female (C) mice; DeAngelo et al. (1999) for DCA in male mice (B) and DeAngelo et al. (2008) for TCA in male mice (B) and Pereira (1996) for DCA and TCA in female mice (D).

*p < 0.05; **p < 0.01; ***p < 0.001. Compared with corresponding control group.

BCA = bromochloroacetic acid, male mice trend = p < 0.001; BDCA = bromodichloroacetic acid, male mice trend = p < 0.001, female mice trend = p < 0.001; DBA = dibromoacetic acid, male mice trend p < 0.001, female mice trend = p = 0.019; DCA = dichloroacetic acid, male mice trend = p < 0.001, female mice trend = p < 0.001; TCA = trichloroacetic acid, male mice trend = p < 0.01, female mice trend p < 0.001.

Results are shown for bromine-containing HAAs in male mice (Panel A), chlorine-containing HAAs in male mice (Panel B), bromine-containing HAAs in female mice (Panel C), and chlorine-containing HAAs in female mice (Panel D).

The NTP and DeAngelo studies were 2 years in duration and the Pereira studies were 1.5 years in length. Trend refers to a positive trend and not the shape of the dose-response curve. Trends were not reported by the authors for DCA and TCA, but NTP calculated trends based on the Cochran-Armitage test (indicated by square brackets [ ] around “Trend”). In the NTP studies, BCA and BDCA were not tested at 50 mg/L and DBA was not tested at 250 mg/L. For the chlorine-only HAAs in males (C), the doses for DCA were 500, 1,000, 2,000, and 3,500 and for TCA they were 50 and 500 mg/L. In females (D), DCA was tested at 260, 860, and 2,600 mg/L and TCA was tested at 330, 1,100, and 3,300 mg/L (equimolar doses for DCA and TCA).

In a stop-exposure study by Wood et al. (2015), 4-week-old mice were exposed to dichloroacetic acid in the drinking water for 10 weeks and then maintained on deionized water until 98 weeks of age for a total observation period of 94 weeks. In male mice, significant increases in the incidence of hepatocellular adenoma, carcinoma, and adenoma or carcinoma or hepatoblastoma (combined) were induced at the high dose (3,500 mg/L) with a significant positive trend for all three analyses. Female mice had significantly increased incidences of hepatocellular adenoma or carcinoma or hepatoblastoma combined at 1,000 mg/L and 2,000 mg/L with a significant positive trend. Wood et al. (2015) noted that the tumor incidence and number induced by the high dose level in their study were ≥85% of the same findings seen after continuous lifetime exposure, indicating that early life exposure may be as carcinogenic as lifetime exposure.

Dichloroacetic acid significantly increased the incidence of hepatocellular neoplasms in male rats as reported in two studies described in the same publication (DeAngelo et al. 1996) that differed slightly in duration; in the study with a duration of 103 weeks, both the incidence of hepatocellular carcinoma and the combined incidence of hepatocellular adenoma and carcinoma were significantly increased at a dose of 2,500 mg/L, and in the second study with a duration of 100 weeks, the combined incidence of hepatocellular adenoma and carcinoma was significantly increased at a dose of 500 mg/L. A non-significant increase in hepatocellular adenoma and carcinoma was observed in male rats exposed to 500 mg/L (adenoma: 21% vs. 4% controls; carcinoma: 10% vs. 0% controls) in a 104-week study and to 2,400 mg/L (adenoma: 26% vs. 0% controls; carcinoma: 4% vs. 0% controls) at 60 weeks (Richmond et al. 1995), which provides some support for the findings in the DeAngelo study.

Trichloroacetic acid was also tested in multiple studies (11 studies reported in 7 publications) in male and female mice but with only one study reporting results for male rats. In male mice, significantly increased incidences of hepatocellular adenoma and carcinoma were induced in two drinking water studies, one tested a single dose of 4,500 mg/L for 2 years and a multi-dose study reported significantly increased incidences after 1 year at 5,000 mg/L and after 2 years at 500 mg/L (DeAngelo et al. 2008), and a single-dose study (Herren-Freund et al. 1987) used a dose of 5,000 mg/L for 61 weeks. Significantly increased incidences of hepatocellular adenoma and carcinoma in male mice was observed at a much lower dose (500 mg/L) in the only study (multi-dose 50, 500 mg/L) that tested for carcinogenicity at doses less than 4,500 mg/L) (DeAngelo et al. 2008) (see Figure 4-1A). Bull et al. (1990) reported that a few hepatocellular carcinomas were observed in male mice in the mid dose (1,000 mg/L, 2 of 5 animals) and high-dose trichloroacetic acid groups (2,000 mg/L, 4 of 11 animals); however, there were only two control mice in this study, which had many study limitations (see Appendix C, Table C-20). In female mice, trichloroacetic acid caused significant increases in the incidence of hepatocellular carcinoma at the mid (1,100 mg/L) and high dose (3,300 mg/L) and adenoma at the high dose (3,300 mg/L) in an ~1.5 year study (Pereira 1996); the incidence of hepatocellular carcinoma was significantly increased at the high dose in a one-year study reported in the same publication. Trichloroacetic acid did not significantly increase the incidence of hepatocellular neoplasms in a 2-year, multi-dose (0, 50, 500, 5,000 mg/L) study in male rats (DeAngelo et al. 1997).

Intraperitoneal injection (2,000 mg/L over two injections in neonatal male and female mice) of trichloroacetic acid did not induce liver tumors in male or female mice at either the 12-month or 20-month observation period (Von Tungeln et al. 2002).

#### Bromine-containing Haloacetic Acids: Dibromoacetic Acid, Bromochloroacetic Acid, Bromodichloroacetic Acid

Exposure to dibromoacetic acid, bromochloroacetic acid, and bromodichloroacetic acid were tested by NTP in male and female mice and male and female rats exposed in the drinking water (NTP 2007a; 2009; 2015). Dibromoacetic acid was given at 50, 500, and 1,000 mg/L and the bromochloro- and bromodichloroacetic acids were given at 250, 500 and 1,000 mg/L. Overall, the studies provide convincing evidence that these chemicals cause malignant tumors in mice: hepatocellular carcinoma in male and female mice and hepatoblastoma in male mice, which were outside the historical control ranges, with positive dose-response trends. Additionally, female mice exposed to bromodichloroacetic acid had a significant increase in hemangiosarcoma in the liver at 1,000 mg/L. A summary of the findings for the different types of hepatocellular neoplasms and combinations is provided in Table 4-3 and the incidences of hepatocellular carcinoma and hepatoblastoma are provided in Figure 4-1 and Figure 4-2. None of the bromine-containing dihaloacetic acids caused a significant increase in the incidence of hepatocellular neoplasms in rats.

Table 4-3 Hepatocellular Neoplasms in Mice Exposed to Bromine-Containing Haloacetic Acids

HAA (Sex) | Hepatocellular Adenoma | Hepatocellular Carcinoma | Hepatocellular Adenoma or Carcinoma (Combined) | Hepatoblastoma | All Liver Neoplasms Combined
DBA (males) | Sign. increases at all doses; positive trend | Sign. increases at high dose; positive trend | Sign. increases at all doses; positive trend | Sign. increases at the mid and high dose; positive trend | Sign. increases at all doses; positive trend
DBA (females) | Sign. increases at mid and high doses; positive trend | Sign. increases at mid and high doses; positive trend | Sign. increases at mid and high doses; positive trend
BCA (males) | Sign. increases at low and mid doses; positive trend | Sign. increases at mid and high doses; positive trend | Sign. increases at all doses; positive trend | Sign. increases at all doses; positive trend | Sign. increases at mid and high doses; positive trend
BCA (females) | Sign. increases at all doses; positive trend | Sign. increase at mid dose; exceeds historical controls at all doses | Sign. increases at all doses; positive trend
BDCA (males) | | Sign. increase at all doses; positive trend | | Sign. increases at all doses; positive trend | Sign. increases at low and high dose; positive trend
BDCA (females) | Sign. increase at all doses; positive trend | Sign. increases at mid and high doses positive trend | Sign. increases at all doses; positive trend | Sign. increase at high dose; positive trend

BCA = bromochloroacetic acid; BDCA = bromodichloroacetic acid; DBA = dibromoacetic acid; sign. = statistically significant.

Figure 4-2

Hepatoblastoma in Male Mice Exposed to Di- and Trihaloacetic Acids

Source: NTP (2007a; 2009; 2015) for the bromine-containing HAA and Wood et al. (2015) for DCA (stop exposure study).

*P < 0.05; **P < 0.01; ***P < 0.001. Compared with corresponding control group.

BCA = bromochloroacetic acid; BDCA = bromodichloroacetic acid, trend P < 0.001; DBA = dibromoacetic acid, trend P < 0.001; DCA = dichloroacetic acid, trend P < 0.001.

Trend refers to a positive trend and not the shape of the dose-response curve. BCA and BDCA were not tested at 50 mg/L and DBA was not tested at 250 mg/L. DCA was tested at 1,000, 2,000, and 3,500 mg/L, but no hepatoblastomas were reported for the 2,000 or 3,500 mg/L doses.

#### Comparison of Liver Neoplasms Findings Across HAAs

Figure 4-1 and Figure 4-2 compare the incidences of different types of hepatocellular neoplasms (carcinoma or hepatoblastoma) in male and female mice. (Data from studies with similar designs and/or similar laboratories were chosen for the graphs.) Incidences of combined liver neoplasms were not plotted because of the high background incidence of total liver neoplasms in controls. In general, no clear differences in the strength of the association with liver cancer by type or number of halogens was observed; however, the data are difficult to interpret because of differences in background carcinoma rates (especially between the chlorine-only haloacetic acids and bromine-containing haloacetic acids) and the high incidences of liver neoplasms in treated animals. There is some evidence to suggest that dichloroacetic acid but not the bromine-containing haloacetic acids cause liver neoplasms in rats. In contrast, the bromine-containing haloacetic acids may be linked to hepatoblastoma. Hepatoblastoma is an aggressive malignancy originating from embryonic liver cells and is a pediatric liver cancer in humans. Incidences of hepatoblastoma were significantly increased in male mice by the three bromine-containing haloacetic acids tested by NTP and in female mice by bromodichloroacetic acid. The only study to observe hepatoblastoma in mice exposed to a chlorine-only haloacetic acid was the stop-exposure study (Wood et al. 2015) which found a single hepatoblastoma at the lowest dose in males and none in females. However, the NTP studies also had the most complete necropsies and pathological evaluations of all of the studies reviewed, which might have contributed to identification of these tumors in mice exposed to bromine-containing haloacetic acids.

### 4.3.2 Other Tumors

The occurrence of tumors at multiple organ sites reinforces the evidence that some halogenated acetic acids have systemic carcinogenic activity in addition to the liver (see Table C-9 and Table C-10 in Appendix C). In addition to liver tumors that developed with chronic exposure to the three brominated haloacetic acids tested by NTP in well-conducted studies, dibromoacetic acid (NTP 2007a), bromochloroacetic acid (NTP 2009), and bromodichloroacetic acid (NTP 2015) increased the incidences of neoplasms at organ sites outside the liver in both rats and mice. No increases in the incidence of neoplasms were observed after exposure to chlorine-only haloacetic acids; however, these tumors were reported only in studies conducted by NTP, which included full necropsies. Since most of the non-NTP studies examined only the liver histologically, the presence of tumors at other sites cannot be definitively ruled out (see Section 4.2, Table 4-2, and Appendix C).

Malignant mesothelioma of the peritoneal cavity lining was the only site to be induced by all three bromine-containing haloacetic acids and thus the findings are discussed across haloacetic acids. The findings for the other neoplasms are organized by the specific haloacetic acid. In the NTP studies, dibromoacetic acid was tested at 0, 50 (low), 500 (mid), and 1,000 (high) mg/L and bromochloroacetic acid and bromodichloroacetic acid were tested at 0, 250 (low), 500 (mid) and 1,000 (high) mg/L. The study on bromodichloroacetic acid differs from the other two haloacetic acids tested by NTP in that it was conducted in F344/NTac rats whereas the other two haloacetic acids were tested in F344/N rats. All three of these haloacetic acids were tested in B6C3F_1_ mice. Details on the study designs and findings are provided in Appendix C, Table C-32 to Table C-35, Table C-36 to Table C-39, Table C-52 to Table C-55.

#### Malignant Mesothelioma

Dibromoacetic acid (NTP 2007a), bromochloroacetic acid (NTP 2009), or bromodichloroacetic acid (NTP 2015) (Figure 4-3) increased the incidence of malignant mesothelioma in male rats with drinking water exposure. Both dibromoacetic acid and bromodichloroacetic acid caused significant positive dose-response trends. Tumors caused by exposure to bromochloroacetic acid or dibromoacetic acid were found throughout the peritoneum, including the abdominal wall and serosal organ surfaces; tumors caused by exposure to bromodichloroacetic acid were localized to the tunica vaginalis of the testes. The historical control range for these tumors was exceeded for dibromoacetic acid and bromochloroacetic acid (NTP 2009) at all doses and for dibromoacetic acid and bromodichloroacetic acid at the high dose. The strongest response was found for bromodichloroacetic acid, which significantly increased malignant mesothelioma at all doses, reaching 78% (poly-3 adjusted rate) for male rats exposed to the high dose.

Figure 4-3

Malignant Mesothelioma Incidence in Male Rats Exposed to Bromochloroacetic Acid, Dibromoacetic Acid, or Bromodichloroacetic Acid in Drinking Water

Source: NTP (2007a; 2009; 2015).

*P < 0.05; **P < 0.01; ***P < 0.001, compared with corresponding control group.

BDCA = bromodichloroacetic acid, trend = P < 0.001; DBA = dibromoacetic acid, trend = P < 0.001.

Note: DBA was tested at 0, 50, 500 1,000 mg/L.

Trend refers to a positive trend and not the shape of the dose-response curve. BCA = bromochloroacetic acid, trend not significant.

#### Dibromoacetic Acid

Mononuclear-cell leukemia incidence was significantly increased by exposure to dibromoacetic acid (NTP 2007a) at the high dose in female rats with a positive dose-response trend. Historical control rates can help interpret these findings because the background rates of mononuclear-cell leukemia in F344/N rats are high and variable. The poly-3 adjusted rates for the mid (35%) and high dose (47%) exceeded the historical control ranges in drinking water studies (20% to 30%) and thus increase the confidence that this is an exposure-related response. A significant increase in the incidence of mononuclear-cell leukemia was observed in male rats at the low but not the mid and high dose and no dose-response was observed; the incidence of tumors for the high dose was somewhat lower than the incidence in controls which exceeded the historical control range. The poly-3 adjusted rates for the controls (37%), low (66%), and mid (56%) but not the high dose exceeded the historical control range of 26% to 34% for drinking water studies. Overall, the incidence of mononuclear-cell leukemia in male rats may be related to exposure to dibromoacetic acid but the findings are inconclusive.

Lung adenoma and adenoma or carcinoma (combined) were also significantly increased by exposure to dibromoacetic acid (NTP 2007a) at the mid dose in male mice, and a significant dose response was observed for adenoma. The poly-3 adjusted incidence for lung adenoma or carcinoma at the mid (49%) and high dose (37%) and for adenoma at the mid (38%) and high dose (27%) exceeded the historical control range (12% to 26%) for drinking water studies. For female mice, tumor incidence for lung adenoma or carcinoma at the high dose (15%) exceeded the historical control range of 2% to 12%. A significant dose response for adenoma was observed but none of the pairwise dose comparisons were statistically significant. Overall, the data provided indicate that the lung is a target organ site for dibromoacetic acid with the strongest evidence from male mice.

#### Bromochloroacetic Acid

In addition to causing malignant mesothelioma in male rats, bromochloroacetic acid also increased the neoplasms of the mammary gland in female rats and large intestine in female and male rats.

Bromochloroacetic acid (NTP 2009) administered in the drinking water significantly increased the incidence of multiple mammary gland fibroadenomas in the mid- and high-dose groups in female rat. This haloacetic acid also caused dose-related increases in the incidence of large intestinal adenoma in both male and female rats. Significant increases in incidence (15.5%) were observed at the highest dose in female rats compared to controls. These are rare tumors with a historical control incidence in drinking water studies of 0% and can progress to malignant tumors of the large intestine.

A statistically significant increase in pancreatic islet adenoma in male rats exposed to bromochloroacetic acid was observed in the mid dose groups compared to controls, which exceeded the historical control rates for both drinking water studies (6% to 10%) and studies by all routes (0% to 12%) for the poly-3 adjusted incidence for the 500 mg/L dose (9/50, 22%) (NTP 2009). However, the incidence was similar in the high-dose group (7%) to the concurrent controls (7%) and there were no significant increases in other types of pancreatic islet lesions (e.g., hyperplasia, carcinoma).

#### Bromodichloroacetic Acid

Compared to controls, exposure to bromodichloroacetic acid (NTP 2015) significantly increased the incidence of mammary gland fibroadenoma (in all exposed groups), carcinoma (high dose), adenoma or carcinoma combined (mid and high dose), and all types of neoplasms combined (in all exposed groups) in female rats. Significant dose-response trends were observed for mammary gland carcinoma, fibroadenoma, and adenoma, carcinoma, or fibroadenoma combined.

Bromodichloroacetic acid treatment resulted in an increase of 8% (4/50) over control values (0/50) of large intestinal (cecum, colon, and rectum combined) adenoma in male rats with 2/50 each in the mid- and high-dose groups. No historical control data were available for the F344/NTac strain; however, large intestine tumors are very rare tumors in F344/N rats with a very low incidence of 0/699 for 2013 historical control incidence and 0% to 2% for the 2009 historical control range) (NTP 2015). Overall, the evidence was considered equivocal because of the small numbers of neoplasms in the exposed animals.

Skin tumors, keratoacanthoma, subcutaneous fibromas, and combined incidences of epithelial tumors (i.e., squamous-cell papilloma, keratoacanthoma, sebaceous gland adenoma, basal cell-adenoma, basal-cell carcinoma, or squamous-cell carcinoma [combined]) were significantly increased in male rats exposed to the highest dose of bromodichloroacetic acid (NTP 2015). Positive trends were observed for fibroma, keratoacanthoma, and basal-cell adenoma.

Harderian gland adenoma and adenoma or carcinoma (combined) incidences were significantly increased in the high- and mid-exposure groups in male mice exposed to bromodichloroacetic acid (NTP 2015). Significant positive dose-response trends were observed for adenoma and carcinoma as well as adenoma or carcinoma (combined). The poly-3-adjusted incidences of the combined neoplasms at all dose levels (low dose = 26%, mid dose = 38%, high dose = 51%) exceeded the historical control range of 12% to 14% for drinking water controls and 6% to 24% for all routes.

Increases in the incidence of brain and oral cavity neoplasms were observed after administration of bromodichloroacetic acid in the drinking water. For each tumor type, the increase in the incidence of the neoplasm was small and non-significant but exceeded the historical control range. However, the low number of Fischer 344/NTac historical controls limited further interpretation of these findings. Overall, the evidence is unclear whether these effects are related to treatment.

#### Synthesis across HAAs

Overall, bromodichloroacetic acid appears to have the strongest association with neoplasms in experimental animals because it induced the largest number of different types of neoplasms (liver, malignant mesothelioma, mammary gland, skin, and Harderian gland, large intestine, and possibly neoplasms of the brain and oral cavity). In addition, it appears to have the strongest association with mesothelioma, which was the only neoplasm induced by all three bromine-containing haloacetic acids. Bromochloroacetic acid induced similar types of neoplasms as bromodichloroacetic acid—mesothelioma and mammary gland tumors—whereas the bromine-only haloacetic acid caused different types of tumors—mesothelioma, lung, and mononuclear-cell leukemia.

### 4.3.3 Transgenic Studies

Two strains of male and female transgenic animals (Tg.AC hemizygous and p53 haploinsufficient mice) were exposed to dichloroacetic acid in drinking water and Tg.AC hemizygous transgenic mice were used to test dichloroacetic acid by dermal exposure. The purpose of these studies was to determine whether these animal models could serve as an adjunct to the 2-year rodent cancer assays for water disinfection by-products, given that dichloroacetic acid is positive in rodent cancer studies. The limitations of these transgenic models were discussed in Section 4.1. The expected neoplasms with exposure to carcinogens that affect the p53 gene are lymphoma or sarcoma in p53 haploinsufficient mice and squamous-cell papilloma or carcinoma of the skin or forestomach in Tg.AC hemizygous mice (Eastmond et al. 2013; Tennant et al. 2001).

One publication reported testing dichloroacetic acid administered in the drinking water in males and females of both strains of transgenic animals with two different study durations (NTP 2007b). After 41 weeks of exposure, dichloroacetic acid induced significant incidences of female Tg.AC hemizygous mice with multiple squamous-cell papilloma of the forestomach and lung alveolar/bronchiolar adenoma in males. No neoplasms or preneoplasms were significantly increased in p53 haploinsufficient mice.

Two dermal exposure studies of dichloroacetic acid were conducted in male and female Tg.AC hemizygous mice (NTP 2007b). Dermal exposure to dichloroacetic acid induced increased incidences of squamous-cell papilloma and epidermal hyperplasia of the skin at the site of application in both sexes. Although these increases were significant, this model is susceptible to false-positive findings of squamous-cell papilloma of the skin. It is not possible to distinguish dichloroacetic acid carcinogenic effects in this model system from a non-carcinogenic effect that leads to skin irritation and false-positive results.

Though these model systems are not ideal and cannot be used directly to interpret the carcinogenic potential in experimental animals, the presence of neoplasms at the site of application offers evidence not only of increased incidences but also of a specific location where the exposure occurred and further supports the relationship of the results to treatment with dichloroacetic acid.

### 4.3.4 Initiation-promotion Studies

Five initiation-promotion studies were identified that tested dichloroacetic acid, trichloroacetic acid, and monoiodoacetic acid. Dichloroacetic acid or trichloroacetic acid were administered in drinking water as a promoter in two sets of studies. In one set of studies, female mice were initiated by an intraperitoneal injection of N-methyl-N-nitrosourea (MNU) (Pereira et al. 1997). Dichloroacetic acid and trichloroacetic acid both significantly increased the multiplicity of hepatocellular adenomas and dichloroacetic acid significantly increased the multiplicity of foci of altered hepatocytes. In the second set of studies, male mice were injected intraperitoneally with ethylnitrosourea (ENU) (Herren-Freund et al. 1987). Dichloroacetic acid and trichloroacetic acid both significantly increased the incidence of hepatocellular adenoma and carcinoma at 2,000 and 5,000 mg/L above that caused by ENU alone. Further, 5,000 mg/L of either haloacetic acid alone, without ENU, significantly increased hepatocellular adenoma and carcinoma.

Monoiodoacetic acid was administered by dermal application as a promoter to mice (sex not reported) that were initiated by dermal application of 7,12 dimethylbenz[a]anthracene (DMBA) (Gwynn and Salaman 1953). Monoiodoacetic acid significantly increased skin papillomas (exact histological classification not reported) in the high-dose group when compared to either acetone or acetic acid controls.

Only the Herren-Freund et al. (1987) initiation-promotion study included groups without the initiator being administered. The remaining initiation-promotion studies only examined the added effect of haloacetic acids to an already established carcinogenic process and so are not directly interpretable as to animal carcinogenicity (Gwynn and Salaman 1953; Pereira et al. 1997).

## 4.4 Synthesis

The evidence for the carcinogenic potential of haloacetic acids in experimental animals is strong as numerous studies have shown significant increases in the incidences of neoplasia from exposure to several haloacetic acids. All haloacetic acids, except for the monochloroacetic acid, induced significantly increased incidences of liver neoplasms in mice or rats, which is consistent with a possible common carcinogenic mode of action (see Table 4-4).

Dichloroacetic acid and trichloroacetic acid induced hepatocellular adenoma and carcinoma in both sexes of B6C3F_1_ mice, and in male Fischer 344 rats exposed to dichloroacetic acid.

Dibromoacetic acid induced hepatocellular adenoma and carcinoma in male and female mice, hepatoblastoma and lung tumors in male mice. In female rats, it induced mononuclear-cell leukemia and in male rats, malignant mesothelioma.

Bromochloroacetic acid caused tumors at several tissue sites in both rats and mice. It induced treatment-related malignant mesothelioma and adenoma of the large intestine in male rats, multiple fibroadenomas of the mammary gland in female rats, hepatoblastoma in male mice and hepatocellular adenoma and carcinoma in male and female mice.

Bromodichloroacetic acid had the most treatment-related cancer sites in both rats and mice. Male mice had treatment-related incidences of adenoma, adenoma or carcinoma (combined) of the Harderian gland, hepatoblastoma, and hepatocellular carcinoma. Female mice had increased incidences of hepatoblastoma, and hepatocellular adenoma and carcinoma. Male Fischer 344/NTac rats had increased incidences of malignant mesothelioma, epithelial tumors of the skin (combined) and subcutaneous fibroma, which typically does not progress to a malignancy. Female rats had treatment-related increases in incidences of fibroadenoma (includes multiple) and carcinoma of the mammary gland.

The mechanisms by which haloacetic acids might induce cancer are discussed in Section 6 and overall conclusions for the carcinogenicity of haloacetic acids are reported in Section 8.