# 3 Disposition and Toxicokinetics

Disposition and toxicokinetics refer to how a chemical can enter and leave the body, what happens to it while it is in the body, and the rates of these processes. Disposition includes absorption, distribution, metabolism and excretion (ADME: Sections 3.1 to 3.3) while toxicokinetics (Section 3.4) refers to the mathematical description of the time course of disposition of a chemical in the body. A synthesis of the data is provided in Section 3.5.

Overall, the data indicate that the haloacetic acids are well absorbed following oral exposure, widely distributed, and excreted unchanged or as metabolites in the urine, or exhaled as carbon dioxide (CO_2_). However, there are marked differences in disposition among these compounds that are related to both the number and types of halogen atom substitutions. Disposition studies in humans were available only for dichloro- and trichloroacetic acid while disposition data in experimental animals were available for most of the chlorinated and/or brominated acetic acids as well as some mixtures of these compounds. No disposition studies were identified for the iodinated acetic acids. The mechanistic implications of these data are discussed in Section 6.

## 3.1 Absorption

Haloacetic acids are rapidly and extensively absorbed from the gastrointestinal tract in humans and experimental animals (IARC 2004a; 2004b; 2013a; 2013b; 2014a; 2014b; NTP 1992; 2007a; 2009; 2015; USEPA 2003; 2011a). Dermal absorption also occurs, but it is a minor route of exposure compared with ingestion. Absorption studies in humans and experimental animals are briefly reviewed below.

### 3.1.1 Human Studies

Ingestion is the primary exposure pathway for di- and trihaloacetic acids because their chemical and physical properties (i.e., low volatility and high polarity) limit inhalation and dermal exposures (Cardador and Gallego 2011; Kim and Weisel 1998). Peak plasma concentrations were reached within 15 minutes to 1.5 hours following ingestion (Cardador and Gallego 2011; Curry et al. 1991; Froese et al. 2002; Kim et al. 1999; Rogers 1995; Stacpoole et al. 1998). However, oral bioavailability of dichloroacetic acid in human volunteers (eight men and eight women) was highly variable (27% to 100% of a single 2 mg/kg dose) but less than 10% when administered at 20 μg/kg for 14 days (Schultz and Shangraw 2006).

Cardador and Gallego (2011) reported that ingestion accounted for about 94% of the total exposure while inhalation (from aerosol droplets) contributed about 5% and dermal routes about 1% in swimmers (adults and children) and workers exposed to haloacetic acids in outdoor and indoor swimming pools. However, di- and trihaloacetic acids are detectable in urine 5 to 30 minutes after wading or swimming in chlorinated swimming pools (Cardador and Gallego 2011; Kim and Weisel 1998).

Dermal permeability coefficients calculated for dichloro- and trichloroacetic acid in human subjects were very low (0.00002 to 0.008 cm/h) (Kim and Weisel 1998). The in vitro permeability coefficients of chloro-, dichloro-, trichloro-, bromo-, bromochloro-, and dibromoacetic acids in aqueous solution across human skin using diffusion chambers were also very low (0.0011 to 0.0026 cm/h) with lag times of 3.7 to 6.5 hours and the authors concluded that the dermal dose from bathing in water containing these haloacetic acids would be insignificant compared to the estimated ingestion dose (Xu et al. 2002). Cases of accidental exposure to monochloroacetic acid show that it is readily absorbed through the skin and is corrosive to tissues (Kulling et al. 1992; Kusch et al. 1990).

### 3.1.2 Laboratory Animal Studies

All haloacetic acids administered orally to rats individually or in mixtures were detected in plasma within minutes after oral dosing (Saghir and Schultz 2002; 2005; Schultz et al. 1999). Oral bioavailability, mean absorption time (MAT), peak blood concentration, and time to peak blood concentration (T_max_) for di- and trihaloacetic acids in rats are shown in Figure 3-1 and Figure 3-2. These data indicate that oral bioavailability was at or near 100% for trichloro-, bromodichloro-, and chlorodibromoacetic acid but was lower (30% to 81%) for dibromo-, bromochloro-, tribromo-, and dichloroacetic acid due to greater first pass metabolism (Schultz et al. 1999). The oral bioavailability of bromodichloroacetic acid in mice ranged from 28% to 73% and was lower than reported in rats (Merdink et al. 2001). The bioavailability of chloroacetic acids in rats was 100% (Saghir and Rozman 2003). Saghir and Schultz (2002) also showed that the oral bioavailability of dichloroacetic acid increased with dose and also increased in glutathione S-transferase zeta (GST-ζ)-depleted rats due to decrease in GST-ζ mediated metabolism (see Figure 3-3 and Section 3.3). Maximum blood concentrations generally occurred around 1 hour for all di- and trihaloacetic acids, with the exception of dichloroacetic acid (8 hours) (Schultz et al. 1999). Maximum blood concentrations (molar basis) for the trihaloacetic acids were about 1.5 to 6 times greater than the corresponding dihaloacetic acids and reflect the relative bioavailability.

Figure 3-1

Oral Bioavailability and Peak Blood Concentration of Di- and Trihaloacetic Acids in Rats

Source: Schultz et al. (1999).

Figure 3-2

Mean Absorption Time and Time to Peak Blood Concentration of Di- and Trihaloacetic Acids in Rats

Source: Schultz et al. (1999).

Figure 3-3

Oral Bioavailability of Dichloroacetic Acid in Naïve and GST-ζ-depleted Rats

Source: Saghir and Schultz (2002).

Rats rapidly absorbed (within 15 minutes) over 95% of the applied dermal dose of monochloroacetic acid from the site of application (Saghir and Rozman 2003). However, much of the absorbed monochloroacetic acid was sequestered in deeper skin layers and served as a “depot” for continued absorption over the course of several hours. No other dermal studies were identified.

## 3.2 Distribution

The degree of reversible plasma protein binding for haloacetic acids is concentration, species, and haloacetic acid dependent. Haloacetic acids show rapid and uniform distribution outside the vascular system to all body tissues with tissue:blood partition coefficients of the unbound fraction generally close to unity. Blood concentration-time profiles, blood:plasma ratios, plasma protein binding, volume of distribution, and tissue distribution data are discussed below.

### 3.2.1 Blood Concentration-time Profiles

Following i.v. (intravenous) dosing in rats, the blood concentrations of di- and trihaloacetic acids (brominated and chlorinated forms) show a short distribution phase followed by a rapid log-linear decline with most concentrations reaching the detection limit within 12 hours (Schultz et al. 1999). Trichloroacetic acid was an exception with detectable blood concentrations after 24 hours. A similar pattern was seen after oral dosing; however, the dihaloacetic acids, particularly dichloroacetic acid, displayed a more complex plasma concentration-time profile characterized by multiple peaks appearing long after the initial absorption phase (Saghir and Schultz 2002; 2005; Schultz et al. 1999). This pattern was not due to enterohepatic recirculation (Schultz et al. 1999). Discontinuous absorption (i.e., region-dependent absorption) from the GI tract was proposed as a possible explanation (Saghir and Schultz 2002). The data suggest that dichloroacetic acid, and possibly other dihaloacetic acids, were absorbed in the upper portion of the GI tract to a higher degree than the trihaloacetic acids (Saghir and Schultz 2002; 2005).

### 3.2.2 Blood:plasma Ratios and Protein Binding

Blood:plasma ratios in rats were close to unity for the dihaloacetic acids and indicate near equal distribution between erythrocytes and plasma (Schultz et al. 1999). Blood:plasma concentration ratios for trihaloacetic acids were lower (0.66 to 0.82) and indicate preferential distribution to plasma. Monochloroacetic acid did not show significant binding to erythrocytes or hemoglobin but did bind to plasma proteins (Kaphalia et al. 1992).

Dihaloacetic acids exhibited much lower plasma protein binding in rats (6% to 11% bound) compared to trihaloacetic acids (50% to 80% bound) (Schultz et al. 1999). In addition, in vitro studies of trichloroacetic acid (doses of 0.01 μg/mL to 1,000 μg/mL) found that humans have higher plasma binding capacity (75% to 87%) compared to rats (38% to 67%), dogs (54% to 65%), or mice (19% to 55%) (Lumpkin et al. 2003; Templin et al. 1995). The higher binding capacity in humans was attributed to more binding sites and slightly higher albumin concentrations (Lumpkin et al. 2003). Higher plasma protein binding increases residence time in the blood and reduces the proportion available for uptake by the tissues. Binding of trichloroacetic acid to plasma proteins is also nonlinear due to partial saturation of plasma binding at high doses in humans, rats, and mice (Lumpkin et al. 2003; Yu et al. 2000).

Both trichloro- and dichloroacetic acid formed adducts to hemoglobin and albumin in rats and mice, but much of the label associated with protein adduction could be accounted for by metabolic incorporation into the amino acid pool and subsequent de novo protein synthesis (Stevens et al. 1992). Mice incorporated a greater portion of the label into proteins than rats, which is consistent with a greater metabolic rate in the mouse. In contrast, Styles et al. (1991) did not find evidence of covalent binding of trichloroacetic acid to DNA or plasma proteins, and very little covalent binding was detected in the liver of mice.

### 3.2.3 Volume of Distribution

Schultz and co-workers tested seven haloacetic acids in rats and did not find any statistically significant difference in steady-state apparent volume of distribution (ranging from 400 mL/kg to 881 mL/kg) (Schultz et al. 1999). This range of values is comparable to the total body water volume of rats, suggesting that haloacetic acids evenly distribute outside of the vasculature and are not highly sequestered in peripheral tissues (Schultz et al. 1999). In addition, the similar volume of distribution across haloacetic acids, despite large differences in plasma protein binding, suggests that differences in protein binding are matched in peripheral tissues. Similarly, mice exposed i.v. to 5 mL/kg to 100 mg/kg of bromodichloroacetate had a steady-state volume of distribution of about 380 mL/kg to 518 mL/kg (also consistent with distribution to total body water) and a blood:plasma ratio of 0.88 (Merdink et al. 2001). However, the volume of distribution for dichloroacetic acid in humans (190 mL/kg to 337 mL/kg following 10 mg/kg or 20 mg/kg i.v., respectively) was much lower than in rats (932 mL/kg, 100 mg/kg dose) and is consistent with greater plasma protein binding in humans (Lukas et al. 1980).

### 3.2.4 Tissue Distribution

Abbas and Fisher (1997) reported tissue:blood partition coefficients ranging from 0.54 (lung) to 1.18 (liver) for trichloroacetic acid in mice. Following oral doses of various mixtures of mono-, di-, and trihaloacetic acids, tissue concentrations were close to plasma concentrations and indicated a rapid equilibrium between plasma and tissues (Saghir and Schultz 2005). Monochloro- and monoiodoacetic acid distributed rapidly to peripheral tissues, particularly to organs that are rich in sulfhydryl groups, such as the liver and kidney (Hayes et al. 1973; Kaphalia et al. 1992). Distribution patterns were comparable at low (0.1 mmole/kg or ~9.5 mg/kg) and high doses (1 mmole/kg or ~95 mg/kg) of chloroacetic acid in rats (Kaphalia et al. 1992). Saghir et al. (2001) also reported rapid distribution of chloroacetic acid to tissues but distribution was slower at a toxic dose (75 mg/kg) compared to a non-toxic dose (10 mg/kg) in male rats. Overall, these data suggest that tissue:blood partition coefficients of haloacetic acids are close to unity and that they distribute uniformly without any significant sequestering in fat or peripheral tissues.

## 3.3 Metabolism and Excretion

Metabolism of haloacetic acids is complex but is qualitatively similar in humans and experimental animals (IARC 2004a; 2004b; 2014a; 2014b; Stacpoole et al. 1998; USEPA 2003; 2011a). A generalized metabolic scheme is shown in Figure 3-4. Although haloacetic acids share common metabolic pathways and metabolites, there are substantial differences in the extent of biotransformation and elimination between compounds and between species. These inter- and intraspecies differences in metabolism and metabolic capacity may explain differences in susceptibility to toxic effects of haloacetic acids. For example, mice have a higher capacity to metabolize dichloroacetic acid compared to rats (Gonzalez-Leon et al. 1999; Larson and Bull 1992).

Figure 3-4

General Metabolic Pathways for Tri- and Dihaloacetic Acids

Adapted from: IARC (2013a; 2013b; 2014a; 2014b); Xu et al. (1995).

GSTZ1 = glutathione S-tranferase zeta 1, THM = trihalomethane.

The haloacetic acids fall into three broad groups based on their metabolism and renal clearance (Saghir and Schultz 2005; Schultz et al. 1999). These groups are broadly described as (1) low metabolism with moderate renal clearance (e.g., trichloroacetic acid), (2) moderate to high metabolism and high renal clearance (e.g., brominated trihaloacetic acids), and (3) high metabolism and low renal clearance (e.g., dihaloacetic acids). Because of the marked differences in the metabolism of various haloacetic acids, the metabolism and excretion of trihaloacetic acids and dihalo- and monohaloacetic acids are reviewed in separate subsections.

### 3.3.1 Trihaloacetic Acid Metabolism and Excretion

Trihaloacetic acids are metabolized primarily by the microsomal fraction, but metabolism also occurs in the cytosolic subcellular fraction (Austin and Bull 1997; Saghir and Schultz 2005). Cytochrome P450 (CYP)-catalyzed reductive de-halogenation of trihaloacetic acids generates a dihaloacetic acid via a free radical intermediate and is then further metabolized by GSTs or can undergo further reductive dehalogenation to form a monohaloacetic acid (discussed in more detail below) (see Figure 3-4) (Merdink et al. 2000; Saghir et al. 2011; Saghir and Schultz 2005; Stacpoole et al. 1998). There is limited evidence for the direct decarboxylation of bromodichloroacetic acid to form CO_2_ and a trihalomethane (Austin and Bull 1997; Xu et al. 1995). Pharmacokinetic simulations suggest that dichloroacetic acid forms slowly from trichloroacetic acid and is then rapidly metabolized and eliminated, resulting in generally nondetectable levels of dichloroacetic acid in the blood (Merdink et al. 1998).

Trichloroacetic acid is the least metabolized haloacetic acid in humans and experimental animals. Allen and Fisher (1993) estimated that in humans, 93% of trichloroacetic acid was excreted unchanged in urine while Paykoc and Powell (1945) reported that about 75% of an i.v. dose (1.5 to 3 g) administered to six patients was excreted unchanged in the urine after 10 days. Metabolism data in rats and mice show that about 45% to 84% of trichloroacetic acid is excreted unchanged in the urine after 24 to 48 hours, and the percent of unchanged trichloroacetic acid in the urine increases with dose (Green and Prout 1985; Larson and Bull 1992; Schultz et al. 1999; Xu et al. 1995; Yu et al. 2000). Metabolites detected in the urine of rodents exposed orally to trichloroacetic acid include dichloroacetic acid, monochloroacetic acid, glyoxylic acid, glycolic acid, oxalic acid, and some unidentified metabolites and accounted for only 7% to 13% of the administered dose (Larson and Bull 1992; Xu et al. 1995). About 4% to 15% was metabolized to CO_2_ and about 1% to 8% was excreted in the feces (Green and Prout 1985; Larson and Bull 1992; Xu et al. 1995; Yu et al. 2000).

The metabolism of other trihaloacetic acids (i.e., bromodichloro-, chlorodibromo-, and tribromoacetic acid) was somewhat different from the pattern seen with trichloroacetic acid and indicates that bromine substitution enhances metabolism (Schultz et al. 1999; Xu et al. 1995). Mice administered 5, 20, or 100 mg/kg bromodichloroacetic acid eliminated 0% to 4% unchanged in the urine, 42% to 45% as urinary metabolites (primarily oxalate), 15% to 30% as CO_2_, and 6% to 10% in the feces (Merdink et al. 2001; Xu et al. 1995). The large difference in urinary excretion of bromodichloroacetic acid between mice and rats was attributed to a more efficient renal tubular reabsorption mechanism and a greater rate of metabolism in mice compared to rats (Merdink et al. 2001).

In vitro data using rat or human microsomes showed that the rate of metabolism of brominated trihaloacetic acids (i.e., bromodichloro-, chlorodibromo-, and tribromoacetic acid) was directly proportional to the number of bromines on the molecule and was further enhanced under reduced oxygen tensions that approximated tissue oxygen levels (Saghir et al. 2011). The brominated trihaloacetic acids were rapidly metabolized by liver microsomes to the dihaloacetic acid product corresponding to loss of a single bromine ion. Reduced oxygen tension (2% oxygen or nitrogen atmosphere) also enhanced the metabolic rate (2% oxygen was selected to be representative of tissue oxygen tension). Reductive dehalogenation of tribromoacetic acid produced dibromoacetic acid in a 1:1 molar ratio with the Br^−^ liberated and there was no evidence of additional metabolism. However, the amount of dibromoacetic acid formed only accounted for about 50% of the consumption of tribromoacetic acid, particularly at higher substrate concentrations, and suggests the possibility of covalent binding and/or nonmetabolic or degradative loss during chemical analysis.

Metabolism and elimination of haloacetic acids is also affected by exposure to mixtures of haloacetic acids or by pretreatment with dichloroacetic acid or trichloroacetic acid (Austin and Bull 1997; Barton et al. 1999; Gonzalez-Leon et al. 1999; Saghir and Schultz 2005). The primary difference in toxicokinetics of di- and trihaloacetic acids in rats was reduced clearance when administered in mixtures rather than as single compounds (discussed in more detail in Section 3.4) (Saghir and Schultz 2002; 2005; Schultz et al. 1999; Schultz and Sylvester 2001). Urinary recovery of trichloro-, bromodichloro-, chlorodibromo-, and tribromoacetic acid was lower in rats when administered in a mixture and is consistent with increased metabolism at relatively low doses (Saghir and Schultz 2005). However, the data also suggest that metabolism of trihaloacetic acids is possibly increased in mixtures when compared to studies where compounds were administered individually at similar doses.

Pretreatment with trichloroacetic acid inhibited both hepatic cytosolic (up to 70%) and microsomal (up to 30%) metabolism of bromodichloroacetic acid in mice but had little effect on dichloroacetic acid metabolism (Austin and Bull 1997). Pretreatment with dichloroacetic acid inhibited cytosolic metabolism of both dichloro- and bromodichloroacetic acid up to 70% but stimulated microsomal metabolism of bromodichloroacetic acid (1.3-fold); however, there was not a concomitant increase in dichloroacetic acid formation (possibly due to the direct decarboxylation of bromodichloroacetic acid to form CO_2_ and bromodichloromethane).

### 3.3.2 Dihalo- and Monohaloacetic Acid Metabolism and Excretion

The dihaloacetic acids are extensively metabolized with low amounts of parent compound excreted in the urine (Gonzalez-Leon et al. 1997; James et al. 1998; Larson and Bull 1992; Lin et al. 1993; NTP 2009; Schultz et al. 1999; Xu et al. 1995). In vivo and in vitro studies show that mice have a significantly higher capacity to metabolize dichloroacetic acid than rats (Gonzalez-Leon et al. 1999; Gonzalez-Leon et al. 1997). When administered as part of a mixture of haloacetic acids, urinary elimination of parent dichloro-, bromochloro-, or dibromoacetic acids were all <0.1% (Saghir and Schultz 2005).

Dihaloacetic acids are primarily metabolized in the cytosol to glyoxylate by a glutathione-dependent process that is catalyzed by GST-ζ (IARC 2013a; 2013b). The relative rates of glyoxylate formation among the three chlorinated/brominated dihaloacetates are: bromochloro- > dichloro- > dibromoacetic acid (Tong et al. 1998). Glyoxylate can be further metabolized to glycolate, oxylate, glycine, and CO_2_ (Figure 3-4). Reductive dehalogenation of dihaloacetic acids to monohaloacetic acids is a minor pathway.

Dichloro-, dibromo-, and bromochloroacetic acid are mechanism-based, irreversible inhibitors of GST-ζ (Anderson et al. 1999; Saghir and Schultz 2002; Schultz and Sylvester 2001). Inhibition of GST-ζ by dihaloacetic acids reduces the extent of metabolism and increases the plasma half-life, and it has been reported in humans, dogs, and rodents (Anderson et al. 1999; Maisenbacher et al. 2013; Saghir and Schultz 2002; 2005; Tong et al. 1998; Tzeng et al. 2000). However, humans have a lower rate of dichloroacetic acid biotransformation by hepatic cytosol than rats or mice (Tong et al. 1998) and human GST-ζ is more resistant to inactivation than rodent or dog GST-ζ (Board and Anders 2011; Maisenbacher et al. 2013). Thus, the use of GST-ζ-depleted rats was shown to be a suitable model for evaluating the kinetics of dichloroacetic acid in humans based on similar in vitro intrinsic metabolic clearance values of low doses in human and rat GST-ζ-depleted liver cytosol (Saghir and Schultz 2002).

In vitro experiments using rat and human hepatic cytosol showed evidence of stereospecific metabolism of bromochloroacetic acid with more rapid elimination of the (−)-bromochloroacetic acid isomer compared to the (+)-bromochloroacetic acid isomer (Schultz and Sylvester 2001). In vivo studies in rats and mice administered a single i.v. dose also showed that the (−) isomer was eliminated about 1.5 to 2.5 times faster than the (+) isomer (NTP 2009). These data suggest that (+)-bromochloroacetic acid is a poor substrate for GST-ζ compared to (−)-bromochloroacetic acid and that another GST isoenzyme may be involved in the metabolism of bromine-substituted dihaloacetic acids.

Several polymorphic variants of GST-ζ have been identified in humans that differ in their susceptibility to inactivation (Board and Anders 2011; Fang et al. 2006; Li et al. 2012). Human liver samples homozygous or heterozygous for GST-ζ 1A exhibited a 3-fold higher capacity to dechlorinate dichloroacetic acid than samples carrying other alleles at a given level of expression (Li et al. 2012). GST-ζ haplotype also influenced dichloroacetic acid kinetics when administered to children with congenital mitochondrial diseases (Shroads et al. 2015). GST-ζ, also known as maleylacetoacetate isomerase (MAAI), is part of the tyrosine catabolism pathway and has been identified as a potential mode of action (see Section 6) (Board and Anders 2011; Schultz et al. 2002; Stacpoole 2011; Stacpoole et al. 2008).

## 3.4 Toxicokinetic Data

The toxicokinetic properties of haloacetic acids in humans and experimental animals are reviewed below. The number and type of halogen substitutions, dose, exposure to mixtures, and age influence the biotransformation and elimination kinetics of haloacetic acids.

### 3.4.1 Human Studies

Most of the toxico- or pharmacokinetic data in humans is for dichloroacetic acid and includes healthy subject volunteers and subjects with various diseases (e.g., lactic acidosis, malaria, liver disease) who were administered dichloroacetic acid as a therapeutic treatment. These studies indicate that the pharmacokinetics of dichloroacetic acid are dose dependent, there are no significant differences between men and women, but there are differences between diseased patients and healthy volunteers (see Appendix B, Table B-1). (Curry et al. 1985; Curry et al. 1991; Henderson et al. 1997; Krishna et al. 1995; Krishna et al. 1994; Krishna et al. 1996; Lukas et al. 1980; Schultz and Shangraw 2006). The distribution phase was generally slower and the plasma T½ was longer in diseased patients. The large interindividual differences in haloacetic acid clearance in humans may be due to polymorphisms that alter GST-ζ activity and expression (Schultz and Shangraw 2006). The urinary excretion half-life of trichloroacetic acid in five healthy volunteers ranged from about 2.1 to 6.3 days and fit a single compartment exponential decay model (Bader et al. 2004). The few human studies that report on the pharmacokinetics of trichloroacetic acid showed a reduced volume of distribution and longer plasma half-life compared to dichloroacetic acid (see Appendix B, Table B-1). Pharmacokinetic modeling of trichloroacetic acid indicates that the volume of distribution is inversely related to body weight, where trihaloacetic acid distributes to about 7% to 14% of body weight in humans, compared to 25% to 51% for rats and 18% to 24% for mice (Allen and Fisher 1993). Systemic clearance of trichloroacetic acid in humans (0.028/hr/kg) also is slower than in rodents (0.045/hr/kg to 0.1/hr/kg). The lower volume of distribution and clearance in humans compared to rodents is likely related to greater plasma protein binding in humans.

### 3.4.2 Experimental Animal Studies

Most of the toxicokinetic studies of the haloacetic acids were conducted in male F344 rats (see Appendix B, Table B-2). The data show that the steady-state apparent volume of distribution is similar for di- and trihaloacetic acids while area under the concentration-time curve and clearance show considerable differences (Schultz et al. 1999). Dihaloacetic acids are primarily eliminated by biotransformation (i.e., nonrenal clearance) with very little parent compound excreted in the urine. As mentioned in Section 3.2, the blood concentration-time profiles for the dihaloacetic acids exhibited multiple peaks that resulted in some uncertainty in the start of the log-linear portion of the profiles and complicated calculations of toxicokinetic parameters. In contrast, trihaloacetic acids exhibited simpler blood concentration-time profiles with reduced metabolism and a higher contribution from renal clearance. Bromine substitution enhanced metabolism and increased both renal (Cl_r_) and nonrenal (Cl_nr_) clearance, especially for the trihaloacetic acids (Figure 3-5). The combination of a similar distribution volume and increasing clearance with bromine substitution resulted in a progressive decrease in elimination half-lives. The data also show that total dose is an important factor for dihaloacetic acids because clearance is dose-dependent due to saturation and inhibition of the GST-ζ metabolic pathway (Figure 3-6).

Figure 3-5

Comparison of Renal and Nonrenal Clearance of an Equimolar I.V. Dose (500 μmol/kg) of Haloacetic Acids in Male Rats

Source: Schultz et al. (1999).

Figure 3-6

Clearance of Dichloroacetic Acid in Naïve and GST- ζ-depleted Male Rats

Source: Gonzalez-Leon et al. (1997); Saghir and Schultz (2002).

When haloacetic acids were administered to rats as mixtures rather than as single compounds, the primary difference was reduced clearance (with the exception of bromochloro- and dibromoacetic acids), suggesting competitive interactions between di- and trihaloacetic acids (Appendix B, Table B-2) (Saghir and Schultz 2005). The inability to show reduced clearance for bromochloro- or dibromoacetic acid when administered as part of a mixture rather than individually may be explained by dose. The available studies that administered these two haloacetic acids as single compounds used high doses (i.e., ≥500 µmol/kg) where metabolic clearance was likely reduced by metabolic saturation and/or GST-ζ depletion. The primary effect of GST-ζ-depletion for both mixtures and single compounds was reduced clearance of the dihaloacetic acids (Figure 3-7a). In contrast, GST-ζ depletion did not affect clearance of trihaloacetic acids (Figure 3-7b). In addition, data for bromochloroacetic acid, a chiral molecule, show stereospecific metabolism with faster elimination of the (−) stereoisomer compared to the (+)-stereoisomer (Figure 3-8). James et al. (1998) showed that the peak plasma concentrations and area under the concentration-time curve were 5- to 6-fold higher in old rats while the elimination half-life was almost 2-fold slower compared to young rats (Appendix B, Table B-2).

Figure 3-7

Clearance of Dihaloacetic Acids (A) and Trihaloacetic Acids (B) Administered as Mixtures of Di- and Trihaloacetic Acids at Equimolar I.V. Doses (25 μmol/kg) to Male Rats

Source: Saghir and Schultz (2005).

Figure 3-8

Stereospecific Clearance of an I.V. Dose (520 μmol/kg) of (−), (+)-Bromochloroacetic Acids Administered to Naïve and GST-ζ-depleted Male Rats

Source: Schultz and Sylvester (2001).

The clearance values reported for the di- and trihaloacetic acids indicate that there are marked differences in the degree of tubular secretion and reabsorption (Schultz et al. 1999). The adjusted renal clearance values for the trihaloacetic acids approached or exceeded the glomerular filtration rate (GFR) for rats, suggesting tubular secretion is an important factor for the renal clearance of trichloroacetic acids. In contrast, adjusted renal clearance values for the dihaloacetic acids are much lower than the GFR (i.e., similar to the urine flow rate) and indicate that tubular reabsorption is important. Thus, the data support the proposition that urinary excretion of trihaloacetic acids is controlled by tubular secretion while urinary excretion of dihaloacetic acids is controlled by tubular reabsorption in rats.

Toxicokinetic data in mice were limited to a few studies with dichloro- and trichloroacetic acid and one study each with dibromo-, bromochloro-, and bromodichloroacetic acid (Appendix B, Table B-3). Although mice have a higher capacity to metabolize dichloroacetic acid than rats and appear to be less susceptible to GST-ζ inhibition, the available data in mice are generally consistent with the rat data (i.e., relative rate of clearance of dichloro- > bromodichloro- > trichloroacetic acid) (Gonzalez-Leon et al. 1999; Larson and Bull 1992; Merdink et al. 2001). Elimination kinetics for bromodichloroacetic acid in mice differed from that in rats and is best illustrated by comparing renal clearance (Merdink et al. 2001). Renal clearance adjusted for protein binding in mice suggested a very efficient tubular reabsorption process. In contrast, tubular secretion was the dominant renal process in rats (Merdink et al. 2001; Schultz et al. 1999).

Pretreatment with trichloroacetic acid had no appreciable effect on the toxicokinetics of a challenge dose of either trichloroacetic acid or dichloroacetic acid in mice (Gonzalez-Leon et al. 1999; Schultz et al. 2002). In contrast, pretreatment with dichloroacetic acid caused a significant increase in the blood concentration-time profile and reduced the clearance of dichloroacetic acid (Gonzalez-Leon et al. 1999). However, the impact of dichloroacetic acid pretreatment on clearance in mice was not as great as that observed in rats. As in rats, age was also shown to be an important factor (Schultz et al. 2002). Clearance of dichloroacetic acid in aged control mice was about 25% of that measured in young control mice. However, compared to age-matched controls, clearance was reduced in young but not aged mice, with a maximum effect observed at 16 hours or less recovery time (see Appendix B, Table B-3).

## 3.5 Summary and Synthesis

Haloacetic acids, especially dihaloacetic and trihaloacetic acids, have many similarities for absorption, distribution, metabolism, and excretion, although differences may exist due to different numbers of halogens on the alpha carbon or the presence of bromine atoms. The findings for absorption, distribution, metabolism, and excretion for haloacetic acids in general and for dihaloacetic and trihaloacetic acids as a class are summarized in Table 3-1 and similar information for seven individual haloacetic acids in Table 3-2. Absorption after oral ingestion is approximately 100% for trihaloacetic acids in rats, but lower absorption has been reported for bromodichloroacetic acid in mice and for dihaloacetic acids in general in both humans and rats. Once absorbed, haloacetic acids distribute rapidly and uniformly outside the vascular system and tissue:blood partition coefficients are near unity, although binding of trihaloacetic acids to plasma proteins can increase blood concentrations, particularly in humans compared with experimental animals. Blood concentrations decrease rapidly with a log-linear decline within 12 hours of i.v. injection. Metabolism of trihaloacetic acids involves both microsomal and cytosolic subcellular fractions although the primary pathway for trihaloacetic acids is through cytochrome P450-catalyzed reductive dehalogenation to generate a dihaloacetic acid via a free radical intermediate. Further metabolism of dihaloacetic acids to glyoxylate and other urinary metabolites (see Figure 3-4) results from a glutathione-dependent process catalyzed by GST-ζ. Elimination for all haloacetic acids is mainly through the urine, although some metabolism to carbon dioxide with elimination from the lungs is possible. Dihaloacetic acids inhibit their own metabolism by inhibiting GST-ζ, thus slowing elimination, but GST-ζ in humans is more resistant to inactivation than in rats and mice. Haloacetic acids can be broadly described by three patterns of elimination: (1) high metabolism and high renal clearance (bromodichloro-, chlorodibromo-, and tribromoacetic acids), (2) high metabolism and low renal clearance (dihaloacetic acids), and (3) low metabolism with moderate renal clearance (trichloroacetic acid). In general, trichloroacetic acid is an outlier compared with other trihaloacetic acids, with greater binding to plasma proteins, lower volume of distribution, and lower metabolism.

Table 3-1 ADME Information for Haloacetic Acids in General and for Trihaloacetic and Dihaloacetic Acids as a Class

HAA | Absorption | Distribution | Metabolism | Excretion
All HAAs | Rapidly absorbed from the GI tract following ingestion | Rapid and uniform distribution to all body tissues Tissue:blood partition ~1 Apparent volume of distribution in rats not significantly different for 7 HAAs below | Rodents: Ultimate metabolites glyoxylic acid, glycolic acid, oxalic acids, glycine, unknown metabolites Substantial differences in extent of biotransformation among species but overall metabolism qualitatively similar in humans and animals | Substantial differences in extent of elimination among species
Trihaloacetic acids (Tri-HAAs) | ND | Overall: Rapid log-linear decline in blood concentrations to below LoD within 12 h (except TCA) Rats: Plasma protein binding 50% to 80% Blood:plasma ratio 0.66–0.82 Maximum blood concentrations ~1.5–6 times greater for tri-HAAs than di-HAAs | Overall: P450 metabolism in microsomes to dihaloacetic acid via dihaloacetic radical In vitro: Rate of metabolism directly proportional with number of bromines Rodents: Moderate to high metabolism for brominated tri-HAAs | Rodents: High renal clearance for brominated tri-HAAs Rats: Urinary excretion of tri-HAAs is controlled by tubular secretion
Dihaloacetic acids (Di-HAAs) | ND | Overall: Rapid log-linear decline in blood concentrations to below LoD within 12 h Rats: Plasma protein binding 6%–11% Blood:plasma ratio ~1 | Overall: GST-ζ metabolism in cytosol to glyoxylic acid (BCA > DCA > DBA); reductive dehalogenation to monohaloacetic acids is a minor pathway Rodents: High metabolism DCA, BCA, DBA irreversibly inhibit GST-ζ | Rodents: Low renal clearance; low amounts of parent compounds in urine Rats: Urinary excretion of di-HAAs is controlled by tubular reabsorption

BCA = bromochloroacetic acid; DBA = dibromoacetic acid; DCA = Dichloroacetic acid; GST-ζ = glutathione S-transferase zeta; HAA = haloacetic acid; LoD = limit of detection; ND = no data; TCA = trichloroacetic acid.

Table 3-2 ADME Information for Individual Haloacetic Acids

Individual HAAs | Absorption | Distribution | Metabolism | Excretion
Trichloroacetic (TCA) | Rats: ~100% | Humans: Volume of distribution lower than in rodents, possibly due to greater plasma protein binding (75%–87%) in humans Rats: Blood levels still detectable after 24 h V_d_ = 782 mL/kg Mice: V_d_ = 571 mL/kg | Overall: Least metabolized HAA in humans and animals Rats: Low metabolism | Humans: Urinary clearance half-life 2.1–6.3 days; clearance slower than in rodents; 75%–93% excreted unchanged Rats: Moderate renal clearance
Bromodichloroacetic (BDCA) | Rats: ~100% Mice: 28%–73% | Rats: V_d_ = 730 mL/kg Mice: V_d_ = 518 mL/kg | Rodents: Greater rate of metabolism in mice compared with rats | Rodents: Urinary excretion higher in rats than mice, likely due to more efficient renal tubular reabsorption in mice
Chlorodibromoacetic (CDBA) | Rats: ~100% | Rats: V_d_ = 636 mL/kg | ND | ND
Tribromoacetic (TBA) | ND | Rats: V_d_ = 449 mL/kg | ND | ND
Dichloroacetic (DCA) | Humans: Variable from <10% to 100% Rats: 81% | Rats: Complex concentration-time profile with multiple peaks V_d_ = 618 mL/kg Mice: V_d_ = 548, 497 mL/kg | Humans: Human GST-ζ more resistant to inhibition Relative rates: Mice > rats > humans | Humans: Large interindividual variations in clearance may be due to GST-ζ polymorphisms
Bromochloroacetic (BCA) | Rats: 47% | Rats: V_d_ = 881 mL/kg | In vitro: Metabolism more rapid for (–)-BCA compared with (+)-BCA | ND
Dibromoacetic (DBA) | Rats: 30% | Rats: V_d_ = 400 mL/kg | ND | ND

GST-ζ = glutathione S-transferase zeta; LoD = limit of detection; ND = no data.

Toxicokinetic studies in experimental animals show no significant differences in the apparent volume of distribution among dihaloacetic and trihaloacetic acids while area under the concentration-time curve and clearance show considerable differences. GST-ζ depletion did not significantly affect toxicokinetics of trihaloacetic acids, but did significantly reduce clearance and also increased area under the concentration-time curve for dihaloacetic acids. Dihaloacetic acids and trihaloacetic acids likely compete in metabolic processes because the primary effect on haloacetic acid toxicokinetics when administered as mixtures is reduced clearance.