# 2 Human Exposure

A significant number of people living in the United States are exposed to haloacetic acids formed as water disinfection by-products because of the widespread use of chlorine-containing disinfectants for water treatment. As noted in the previous section, water disinfection in the United States and worldwide has provided major public health benefits through decreases in infectious diseases and increases in life expectancy that result from providing safe, clean drinking water.

According to EPA, over 48,000 U.S. public water systems provide disinfected water to more than 250 million people, while 10% to 15% of the U.S. population uses private groundwater wells that are typically not disinfected (USEPA 2005; 2015a; 2015b). Thus, the majority of the U.S. population is exposed to mono-, di-, and trihaloacetic acids found as water disinfection by-products. Ingestion of chlorinated drinking water is the most common exposure route for haloacetic acids (HAAs) for the general public, but inhalation and dermal exposure also can occur. The chemical and physical properties of HAAs (i.e., low volatility and high polarity) limit inhalation and dermal exposures and ingestion accounted for about 94% of total exposure for swimmers in chlorinated swimming pools (Cardador and Gallego 2011; Kim and Weisel 1998) (see Section 3.1.1). Other potential sources of exposure to HAAs for the general public include consumption of beverages prepared with treated water either in the home or commercially, consumption of food prepared with treated water, accidental ingestion of swimming pool or spa water by heavy swimmers or spa users, and in some limited circumstances from point-of-use disinfection. Information on potential occupational exposure to HAAs is limited, but exposure to swimming pool attendants at indoor and outdoor pools has been documented.

## 2.1 Water Treatment and Formation of Disinfection By-products

The presence of HAAs in the United States is well established, but knowledge of the chemical and physical processes that lead to their formation is important to help control their levels as required by law. Source water, either groundwater or surface water, contains organic carbon that reacts with chlorine-based disinfectants. Elevated levels in source water of bromide and iodide from anthropogenic and natural sources will likely shift production of HAAs during water disinfection toward more brominated and iodinated species. Minimizing the content of HAAs in finished water provided to consumers is an important goal, and the best current strategy for remediation of HAAs is prevention or reduction of their production. This generally involves reducing the potential precursors present as organic carbon in the source water, but manipulation of conditions for disinfection, such as choice of disinfectant, dose, contact time with water, temperature, and pH can also be effective means to reduce formation. Research into the chemical reactions and intermediate molecules formed also contributes to greater understanding of the process of formation and how to control it.

Water disinfection is regulated by EPA through Surface Water Treatment Rules (SWTRs) that established maximum contaminant level goals (MCLGs) for viruses, bacteria, such as Legionella, and other organisms such as the protozoa species Giardia lamblia and Cryptosporidium. The purpose of water treatment is to remove contaminants and disease-causing agents from drinking water (CDC 2015). The most common steps in conventional water treatment are (1) coagulation and flocculation, (2) sedimentation, (3) filtration, (4) disinfection, and (5) storage (see Figure 2-1) (CDC 2015; USEPA 2016a). In disinfection, application of oxidants (chlorine, chloramine, chlorine dioxide, or ozone) or ultraviolet (UV) light kills disease-causing microorganisms or renders them inactive. Reverse osmosis is another non-chemical water purification method, but its primary use is at the household level rather than by community water treatment facilities other than at desalination plants.

Figure 2-1

Conventional Water Treatment Flow Diagram

Sources: CDC (2015); USEPA (2016a).

## 2.2 Factors That Affect Formation of Disinfection By-products

The factors (see Figure 2-2) that determine the type and amount of disinfection by-products formed during water treatment include (1) the presence of organic matter and inorganic matter in the source water, which is subject to daily as well as seasonal variation in concentration, (2) the disinfecting chemicals used, and (3) the length of time the organic matter is exposed to the disinfecting chemicals, the temperature at which the disinfection process takes place, and the pH of the water during the disinfection process. The organic molecules in source water are often extremely large, complex molecules and intermediate molecules will form as a result of exposure to disinfecting chemicals; further reaction with those chemicals during the disinfection process and storage will result in formation of halogenated by-products, including haloacetic acids.

Figure 2-2

Major Factors Affecting the Formation of Halogenated Disinfection By-products

Organic molecules in source water plus naturally occurring or anthropogenic bromide and iodide react with various chlorine-containing disinfecting chemicals to form halogenated intermediate molecules and ultimately the halogenated HAAs.

HOBr = hypobromous acid; HOCl = hypochlorous acid; HOI = hypoiodous acid; NOM = natural organic matter.

### 2.2.1 Characteristics of Source Water

The major characteristic of the source water that determines the formation of disinfection by-products is the type and quantity of potentially reactive natural organic matter (NOM) and the inorganic halogen precursors, bromide and iodide. The organic matter found in either surface or groundwater consists of a mixture of organic compounds derived from sources such as terrestrial plants, microbially derived from algae and bacteria, or from anthropogenic sources. The latter class includes pesticides, pharmaceuticals, personal care products, and newer materials such as carbon nanotubes (Nelson 2015). The molecules of NOM in source water that react with chloride, bromide, and sometimes iodide to form HAAs range from very complex, e.g., humic and fulvic acids, to simple amino acids and dicarbonyl acids (Reckhow et al. 2001; Reckhow and Singer 1985; Zhai and Zhang 2011).

Anthropogenic and natural sources of bromide and iodide (see Table 2-1) can increase concentrations of these halide ions in source waters (e.g., due to incomplete removal or non-removal in wastewater treatment plants) and create brominated and iodinated HAAs and other disinfection by-products such as trihalomethanes and bromate (McTigue et al. 2014). Elevated levels of bromide and iodide in source water will likely shift production of HAAs during water disinfection toward brominated and iodinated species.

Table 2-1 Effects of Sources of Bromide and Iodide in Source Water on Haloacetic Acid Formation

Source | Effect on Bromide or Iodide Ion Concentration | Effect on Disinfection By-product Formation | Reference
Coal-fired electric power plants | Increased bromide ion concentration power plant wastewater discharges | Increased brominated HAA species^a^ | McTigue et al. (2014)
Oil and gas production | Bromide ion concentration increased from <0.02 mg/L [<20 µg/L] upstream of oil and gas CWT^b^ to 75 mg/L [75,000 µg/L] downstream of CWT Increased bromide ion concentration in publicly owned treatment works and CWT discharges | Downstream concentration of DBCNM^c^ ranging from 5.7 µg/L–8.7 µg/L Increased brominated disinfection by-product formation^a^ | Hladik et al. (2014) ^d^ Hammer and VanBriesen (2012)
Seawater intrusion | Bromide concentration increased from 38 µg/L to 974 µg/L as seawater content increased from 0% to 2% | HAA9 concentration increased from 39 µg/L to 75 µg/L and disinfection by-product formation shifted from chlorine-containing to bromine-containing species | Ged and Boyer (2014) ^e^
Seawater desalination | Saudi Arabia, Red Sea coast: Bromide concentration in seawater = 60 mg/L [60,000 µg/L]; iodide concentration = 0.05 mg/L [50 µg/L] United States, Tampa Bay: Bromide concentration range in seawater = 49 mg/L–56 mg/L [49,000 µg/L–56,000 µg/L] | Reported HAA9 concentration range in chlorinated seawater = 5.35 µg/L–6.86 µg/L Reported HAA5 concentration range in chlorinated seawater = 69 µg/L–175 µg/L | Kim et al. (2015)
Iodinated X-ray contrast media | Various iodinated X-ray contrast media (iopamidol, iohexol, and iopromide) dissolved in raw river water at concentrations ranging from 3,880 µg/L–4,100 µg/L^f^ | Iodoacetic acid concentrations ranged from 0.5 nM to 9.6 nM [0.09 µg/L–1.8 µg/L] | Duirk et al. (2011) ^e^

^a^ No quantitative data on increases in brominated HAA data were reported.

^b^ CWT = commercial wastewater treatment plant.

^c^ DBCNM = dibromochloronitromethane.

^d^ No data on finished water haloacetic acids were reported.

^e^ Laboratory chlorination study.

^f^ Concentration reported as 5 µM for all contrast media.

### 2.2.2 Characteristics of Disinfection Methods

The choice of disinfection methods is generally based on their effectiveness, including their continued presence as a secondary disinfectant in the water distribution system, their overall cost, and their ease of use by water treatment facilities, but chlorine-containing chemical disinfection is by far the most widely used approach in the United States. The major disinfection methods, i.e., chlorine as either a gas (Cl_2_), liquid (NaOCl), or solid (Ca(OCl)_2_) form; chloramine; chlorine dioxide; ozone; and ultraviolet (UV) irradiation are generally effective as a primary disinfectant. A comparison of the major factors differentiating these disinfection methods is provided in Table 2-2.

Table 2-2 Comparison of Water Disinfection Methods

Disinfectant | Efficacy as Primary Disinfectant | Residual Disinfection in Distribution System | Total HAAs Formation | Other DBPs Formed | Ease of Use; Cost
Chlorine (Cl_2_, HOCl, OCl^-^) | High to intermediate | Yes | High | THMs, HANs^a^ | Easiest method to use for HOCl/OCl^-^; least expensive
Chloramine (NH_2_Cl) | Intermediate | Yes (more effective that chlorine alone) | Intermediate (~1/3 level formed with chlorine)^b^ | HANs^a^ | Requires additional equipment to add ammonia; slightly more expensive than chlorine alone
Chlorine dioxide (ClO_2_) | High to intermediate | No | Intermediate (less than 1/2 level formed with chlorine)^b^ | Chlorite & chlorate (ClO_2_ breakdown products) | Requires more technical skill & requires secondary disinfection; more expense for equipment and chemicals
Ozone (O_3_) | High | No | Low (generally only in presence of Br^-^) | Bromate | Requires more technical skill & requires secondary disinfection; more expense for equipment and chemicals
UV irradiation | High | No | No | No | Requires more technical skill and training & requires secondary disinfection; more expense for equipment and chemicals

HAN = haloacetonitrile; TOC = total organic carbon.

^a^ IPCS (2000).

^b^ Zhang et al. (2000).

### 2.2.3 Effects of Time, Temperature, pH, and Other Factors on Formation of Haloacetic Acids

The initial reaction of chlorine with NOM results in rapid formation of HAAs during the first 4 to 8 hours with approximately 90% of the final concentrations of trichloroacetic acid and dichloroacetic acid formed during the first 24 hours after chlorine is added to water. Formation of dibromoacetic acid may not level off until 18 to 20 hours after chlorination begins. In general, the formation rates for HAAs increase with increasing temperature. Effects of pH on HAA formation can vary, depending on which chlorine species (i.e., hypochlorous acid or hypochlorite ion) predominates. For example, the more active form of chlorine, hypochlorous acid, is present at higher concentrations below pH 7.5 than above. Thus, increasing pH has been associated with decreasing concentrations of HAAs (IPCS 2000). The water disinfection process can be described by the product (CT) of chlorine concentration (C) times contact time (T) (SDWF 2009). Chlorine must be added until competing pathways with reducing compounds in the source water and the combination of chlorine with other molecules are saturated with chlorine and a free chlorine residual is present at what is referred to as the breakpoint for chlorination. Beyond the breakpoint, the remaining free chlorine will disinfect the water and provide a residual for secondary disinfection during storage and distribution.

### 2.2.4 Chemistry of Formation of Haloacetic Acids during Water Disinfection with Chlorine-containing Disinfectants

Proof of the concept that interaction of chlorine-containing disinfectants with natural organic substances in source water can result in formation of HAAs has been achieved by laboratory experiments demonstrating formation of halogenated intermediate molecules that give rise to HAAs from samples of humic acid. Reaction pathways of the reactive forms of chloride with organic matter include oxidation, addition, and electrophilic substitution reactions (Deborde and von Gunten 2008), and most reactions between chlorine and humic acids within NOM result in oxidation of humic acids rather than chlorine substitution (Dickenson et al. 2008).

Research on formation of HAAs and other disinfection by-products supports the formation of a number of potential intermediate molecules from precursors in natural organic matter in source water (Reckhow et al. 2001; Reckhow and Singer 1985; Zhai and Zhang 2011). These smaller intermediate molecules, mostly organic acids (but also substituted phenolic compounds), can give rise to HAAs (Bond et al. 2012; Dickenson et al. 2008).

## 2.3 Remediation of Haloacetic Acids

Remediation of haloacetic acid disinfection by-products can be divided into three general approaches: (1) removal of precursors (i.e., NOM) prior to disinfection, (2) modification of disinfection practices (e.g., altering disinfectant dose, type, or application point in the water treatment process), and (3) removal of disinfection by-products after formation. Table 2-3 summarizes potential methods for remediation of HAAs before, during, and after the water treatment process.

Table 2-3 Methods for Remediation of Haloacetic Acids

Remediation Process | Method Description | Effectiveness/Comments
Removal of precursors prior to disinfection
Coagulation | Addition of metallic salts, e.g., alum, which neutralize negative charges on particles, so they agglomerate and precipitate to remove precursors | 15%–78% removal of precursors by alum coagulation; (typically15%–20%)
Ion exchange | Exchange of ions between aqueous solution and solid phase, e.g., resin, to remove precursors | 52%–72% removal of precursors 52%–80% removal in combination with alum coagulation
Membrane filtration | Size exclusion, electrostatic repulsion, and differences in solute diffusion rates across membranes to remove precursors | 67%–99% removal by nanofiltration, which is most effective for removal of hydrophilic, low-molecular weight precursors
Activated carbon filtration | Reversible physical adsorption by nonspecific forces with preferential removal of hydrophobic NOM | 60%–91% removal of precursors by granular activated carbon (GAC)
Biotreatment (biologically activated carbon) | Enzyme-controlled microbial degradation and adsorption involving growth of a biofilm on sand or activated carbon filter media | Up to 62% removal by bioactive sand; TCA precursors more biodegradable than DCA precursors
Advanced oxidation processes (AOPs) | In situ generation of highly reactive hydroxyl radicals to degrade precursors through fast, non-selective reactions with organic compounds. May include ozone plus UV, ozone plus hydrogen peroxide, or UV plus hydrogen peroxide | Up to 83% removal by O_3_/UV Up to 85% removal by O_3_/H_2_O_2_ with biologically activated carbon
Ozone | Oxidation, bond cleavage, and hydroxyl radical reactions preferentially with aromatic compounds, alkenes, and amines | Relatively ineffective at low ozone concentrations At higher concentrations may increase HAA levels
Modified disinfection practices | Eliminating pre-oxidation or changing the pre-oxidation chemical, e.g., using potassium permanganate, hydrogen peroxide, or ozone as a pre-oxidant rather than pre-chlorination Alternative disinfectants, such as chloramines, chlorine dioxide, ozone, or UV irradiation | No data found on percent effectiveness Alternative methods, particularly ozone and UV, do not leave a disinfectant residual in the distribution system
Removal of HAAs after formation | Filtration using biologically active granular activated charcoal | Up to 99% at early stage of operation (via physical adsorption) but decreased over 3.5-month time period; removal again increased up to 99% after 6 months (via biodegradation) Removal of precursors is greatest when temperatures are high and residual chlorine concentration is low

Source: Bond et al. (2011); Kim and Kang (2008); Singer et al. (2002).

HAAs = haloacetic acids; NOM = natural organic matter; UV = ultraviolet light.

USEPA (2006) reported that 9.6% of plants of all sizes in the United States treating surface water used granular activated carbon (GAC) while only 0.9% of the plants treating ground water used GAC. GAC has been shown to remove 38.5% to 91.2% of bromide ion from water in bench-scale and pilot-scale experiments (Zhang et al. 2015b), thus reducing potential formation of brominated HAAs. Biologically active carbon (BAC), i.e., GAC with a natural bacteria population on its surface, was able to remove up to 100% of HAAs by biodegradation while ozonation removed only 10% to 20% (Ratasuk et al. 2008). BAC was much more effective than sterilized GAC, which would remove HAAs only by adsorption.

The use of home water filters, either pitchers with filters, faucet filters, or whole-house systems, have become more common. A report on home water treatment by USEPA (2005) indicated that more than 4 in 10 homes have some form of home water treatment unit. A study of the effectiveness of point-of-use water filters (Stalter et al. 2016b) concluded that removal of halogenated disinfection by-products by activated carbon-based tap water filters could provide a public health benefit.

## 2.4 Formation in Swimming Pools and Spas and Other Domestic Uses

The disinfection of water for swimming pools and spas also results in formation of HAAs but often at higher levels than in disinfected tap water because of the use of a higher chlorine residual and higher temperatures than in typical water distribution systems (Chowdhury et al. 2014; Parinet et al. 2012). Dichloroacetic acid and trichloroacetic acid are the most abundant HAAs detected in swimming pools (Teo et al. 2015). For U.S. swimming pools disinfected with chlorine, dichloroacetic acid concentrations have been reported to range from 52 μg/L to 6,800 μg/L, and trichloroacetic acid concentrations from 76 μg/L to 1,900 μg/L (Kanan 2010). Additional human precursors (e.g., sweat, urine, hair, cosmetics) can affect the speciation of disinfection by-products formed in swimming pools (Richardson and Postigo 2015). The levels of HAA9 in seawater swimming pools treated with chlorine bleach as disinfectant ranged from 417 μg/L to 2,233 μg/L for different pools tested (Parinet et al. 2012). However, the levels of individual HAAs were generally highest for brominated HAAs, i.e., bromoacetic acid, bromochloroacetic acid, dibromoacetic acid, bromodichloroacetic acid, and chlorodibromoacetic acid, consistent with the presence of bromide in sea water.

The active ingredient in common household bleach is sodium hypochlorite, which is also used in some systems for water disinfection. Thus, use of bleach containing hypochlorite for household cleaning and laundry can produce haloacetic acids and other disinfection by-products observed in disinfected drinking water (EU 2007).

## 2.5 Point-of-use Disinfection

Most laboratory studies of disinfection by-product formation from point-of-use disinfection report trihalomethane occurrence data; only limited data were identified for HAA formation (Lantagne et al. 2008; Lantagne et al. 2010; Smith et al. 2010b; Werner et al. 2016). Iodoacetic acid levels of 9.7 nM to 22.9 nM [1.8 μg/L to 4.3 μg/L] have been reported from use of iodine tincture; bromoiodoacetic acid and diiodoacetic acid were also detected but were not quantified because they were below method detection limits (Smith et al. 2010b).

## 2.6 Other Uses of Haloacetic Acids

Several haloacetic acids have had limited uses medically or in research laboratories; the more extensive commercial uses are listed below. Dichloroacetic acid is used as a chemical manufacturing intermediate (e.g., for glyoxylic acid), in polyethylene terephthalate production, as a skin cauterizing agent, as a medicinal disinfectant (e.g., a substitute for formalin), as a treatment for congenital lactic acidosis, and it has been proposed as a targeted cancer therapeutic agent (IARC 2014a). The main use of trichloroacetic acid in the past was as an herbicide; however, all registrations for this use in the United States were voluntarily canceled by 1992 (some existing stock may have been used after that date). Trichloroacetic acid also has other industrial uses (e.g., surface treatment of metals), and is widely used as a laboratory reagent and as a treatment for dermatological diseases. Chloroacetic acid is used in the manufacture of organic chemicals including cellulose ethers (used mainly for drilling muds, detergents, food, and pharmaceuticals), glycine, thioglycolic acid, dyes, synthetic caffeine, and as a post-emergence contact herbicide and defoliant (PubChem 2016b). Tribromoacetic acid has been used in organic synthesis (HSDB 2009c). Diiodoacetic acid has been used as a chemical intermediate (PubChem 2005). Bromoacetic acid has been used for organic synthesis and abscission of citrus fruit (HSDB 2009). Iodoacetic acid has been used as a food additive and as an intermediate in pharmaceuticals, herbicides, antipyretic, anti-inflammatories, and analgesics (HSDB 2003). Dibromoacetic acid and bromochloroacetic acid were reported to be used only in research (IARC 2013c).

## 2.7 Exposure to Haloacetic Acids

Exposure to HAAs as disinfection by-products affects almost all people living in the United States because the vast majority of water treatment facilities use chlorine-based disinfection methods due to their ease of use and low cost. In addition to ingesting HAAs by drinking plain tap water, humans can also be exposed to HAAs from other beverages prepared with treated water such as tea or coffee or fruit drinks and soft drinks or by ingesting food that came in contact with treated water. Foods, both canned and fresh, are generally washed with or soaked in treated water and are cooked in treated water. Dermal and inhalation exposure from swimming pools and spas where water is disinfected and from occupational exposure also can occur. Occupational exposures to some HAAs can also occur.

Eleven of the 13 HAAs discussed in this monograph have been identified in disinfected water (see Section 2.7.1 and Table 2-4); the remaining two are iodinated molecules formed under experimental conditions. Haloacetic acids (HAAs) and trihalomethanes (THMs) are the largest groups of water disinfection by-products by weight and make up about 50% to 75% of total halogenated disinfection by-products measured and about 25% to 50% of total organic halides measured (Krasner et al. 2016b; Krasner et al. 2006). Both HAAs and total trihalomethanes (TTHMs) are regulated by EPA, and epidemiological studies have tended to use TTHMs as a surrogate for disinfection by-product exposures. HAAs are generally correlated with TTHMs but the ratio between these disinfection by-products may vary depending on water source and methods of disinfection. Relevant epidemiological studies measuring internal exposure to HAAs are not available, in part because of the lack of a specific marker.

Table 2-4 Concentration Ranges for Mono-, Di-, and Trihaloacetic Acids in Tap Water, Finished Drinking Water, and Other Similar Sources

Mono, Di-, or Trihaloacetic Acid | Range (µg/L) | Reference
Chloroacetic acid | 3 (1–11)^a^ | USEPA (2016b) ^b^
Bromoacetic acid | 1.6 (0.59–7.3)^a^ | USEPA (2016b) ^b^
Iodoacetic acid | Up to 1.7 | Richardson et al. (2008)
Dichloroacetic acid | 10.4 (1.3–32) | USEPA (2016b)
Dibromoacetic acid | 2.1 (0.63–12) | USEPA (2016b)
Diiodoacetic acid | –^d^ | –
Chlorobromoacetic acid | BDL^c^–18 | HSDB (2009a); IARC (2013c)
Chloroiodoacetic acid | –^d^ | –
Bromoiodoacetic acid | Up to 1.4^b^ | Richardson et al. (2008)
Trichloroacetic acid | 8 (1.1–32) | USEPA (2016b)
Tribromoacetic acid | 0–approx. 10^e^ | McGuire et al. (2002)
Bromodichloroacetic acid | 5.28–12.2 | HSDB (2009b)
Chlorodibromoacetic acid | BDL^c^–5.37 | HSDB (2009d)

^a^ Median (5th percentile–95th percentile).

^b^ Third Six-Year Review Information Collection Request dataset, https://www.epa.gov/dwsixyearreview/six-year-review-3-compliance-monitoring-data-2006-2011.

^c^ Below detection limit; detection limit not specified.

^d^ No data identified.

^e^ One extreme value of ~20 μg/L was reported.

### 2.7.1 Occurrence of Haloacetic Acids in Treated Water

The highest levels of HAAs have been detected for the molecules chloroacetic acid, dichloroacetic acid, trichloroacetic acid, chlorobromoacetic acid, and bromodichloroacetic acid (Table 2-4). The presence of chlorine atoms in these molecules is expected since chlorination is overwhelmingly the most commonly used water disinfection method in the United States and estimates indicate that about 98% of U.S. water treatment systems use some type of chlorine disinfection process such as chlorine, chlorine dioxide, or chloramine (American Chemistry Council 2016). As described above, a number of sources (Table 2-1) for increased bromide concentrations in source water have been identified.

National occurrence data from the American Water Works Association (AWWA) for HAA5 (the sum of five HAAs—bromoacetic acid, dibromoacetic acid, chloroacetic acid, dichloroacetic acid, and trichloroacetic acid—for 1997 through 2014 and representing 93% of U.S. systems serving populations greater than 100,000 people (collected to assess impacts of the EPA Stage 2 Disinfectants and Disinfection By-products Rule [DBPR]) indicate that 95th percentile HAA5 concentrations have displayed a generally decreasing trend since 2000 (largely due to plants switching from chlorine to chloramines for disinfection) and have been at or below the EPA maximum contaminant level (MCL) of 60 µg/L for HAA5 since 2004 (Seidel et al. 2017). Figure 2-3 presents this information. There is some evidence that smaller facilities have more difficulty in meeting the regulatory limits. Data from EPA collected under the Safe Drinking Water Act (SDWA) national compliance data for the third Six-Year Review (SYR3) for 2006 to 2011 indicated that systems serving fewer than 10,000 people had a 95th percentile HAA5 concentration that remained above the HAA5 60 µg/L MCL throughout the period studied whereas the 95% percentile was below the MCL for systems serving more than 100,000 people (see Figure 2-4). In addition, the 10 highest levels reported for HAA5 based on data from the Environmental Working Group (EWG 2016) were facilities serving fewer than 4,000 persons.

Figure 2-3

National HAA5 Occurrence Data for 1997 through 2014

Source: Adapted from Seidel et al. (2017).

Data are presented for 5th, 25th, 50th, 75th and 95th percentiles for each year from 1997 to 2014 for U.S. water systems supplying more than 100,000 people.

Dashed horizontal line = HAA5 maximum contaminant (MCL) of 60 µg/L.

Figure 2-4

HAA5 Occurrence Data for 2006 through 2011 from EPA Safe Drinking Water Act National Compliance Monitoring for the Third Six-year Review

Source: USEPA (2016b).

Data are presented for 5th, 25th, 50th, 75th and 95th percentiles for each year from 1997 to 2014 for U.S. water systems supplier more than 100,000 people.

Dashed horizontal line = HAA5 maximum contaminant (MCL) of 60 µg/L.

### 2.7.2 Correlation of Haloacetic Acids and Trihalomethanes in Treated Water

In the majority of reported studies, total HAAs (THAAs) have been found to correlate with total trihalomethanes (TTHMs); correlation coefficients ranging from ~0.6 to 0.92 in the majority of studies although a few studies found lower rates, mostly between 0.4 and 0.6 with one outlier of 0.1 (see Figure 2-5). While TTHMs and THAAs or HAA5 have been the primary surrogate measure used in epidemiological studies to estimate exposure to disinfection by-products, concern has been raised for how well these substances can represent the hundreds of disinfection by-products in treated water (Parvez et al. 2011; Plewa and Wagner 2015). No data were identified for correlations between either THMs or HAAs and other disinfection by-products. However, THMs and HAAs are expected to be inversely related to some emerging disinfection by-products (e.g., N-nitrosodimethylamine [NDMA] and iodinated disinfection by-products) because chloramination maximizes their formation and vastly reduces the formation of THMs and HAAs.

Figure 2-5

Correlation Data for Haloacetic Acids and Trihalomethanes in Treated Water

Sources: Ates et al. (2007); Chang et al. (2010b); Hinckley et al. (2005); King et al. (2004); Lee et al. (2001); Malliarou et al. (2005); Nieminski et al. (1993); Nissinen et al. (2002); Parvez et al. (2011); Roccaro et al. (2014); Rodriguez et al. (2007); Villanueva et al. (2003b); Wei et al. (2010).

The ratio of HAAs to THMs is usually around 1:1 but can be higher or lower depending on source water characteristics and disinfection conditions [e.g., Singer et al. (2002) reported that lower chlorination pH tends to favor HAA9 formation while higher pH favors THM formation] (Chang et al. 2010a; Krasner et al. 2006; Liang and Singer 2003; Roberts et al. 2002; Roccaro et al. 2014; Singer et al. 2002; Villanueva et al. 2003a; Weinberg et al. 2002). Individual studies with different ratios between HAAs and THMs suggest as much as a 4-fold spread for the ratio [i.e., ranging from 2:1 for THAA to TTHM (Villanueva et al. 2003a) to 1:2 for the same comparison (Roccaro et al. 2014)].

Extensive data are available for levels of TTHM and HAA5 from municipal water-treatment facilities regulated by EPA (see Section 2.7.1), but the relationship between these disinfection by-products and nonregulated disinfection by-products has not been well established. Disinfection of water involves complex interactions between the disinfecting agents and the organic and inorganic components of the source water, which can include bromide and iodide ions in mildly saline groundwaters from coastal aquifers (Szczuka et al. 2017). For example, Szczuka et al. (2017) measured regulated (trihalomethanes and haloacetic acids) and nonregulated (haloacetonitriles, haloacetamides, and haloacetaldehydes) disinfection by-products formed by chlorination of coastal groundwater samples containing bromide and iodide and found that the haloacetonitriles and the haloacetaldehydes, along with haloacetic acids, were major contributors to the calculated toxicity of the disinfection by-products. Further, Ged and Boyer (2014) measured HAA5 and HAA9 during laboratory chlorination studies of fresh groundwater spiked with up to 2% seawater, which increased the bromide concentration by more than 25-fold and the mass concentration of HAA9 almost doubled due to increased formation of bromine-containing HAAs while the HAA5 concentration stayed the same or decreased (4 of the 6 bromine-containing HAAs are not regulated in HAA5) under the conditions tested. Thus, the continued contaminant monitoring by EPA will be important in better defining control of the regulated disinfection by-products and those that are not currently regulated.

### 2.7.3 Potential Exposure from Beverages Prepared with Treated Water

Beverages that are prepared in the home, such as tea, coffee, or infant formula, or commercially, such as fruit juices and soft drinks, may be prepared with treated water. Several HAAs, primarily dichloroacetic acid, chloroacetic acid, dibromoacetic acid, and bromochloroacetic acid, are quite stable in boiling water with losses of less than 20% after 60 minutes (Raymer and Michael 2010), so home-prepared tea or coffee would have levels of HAAs similar to those in tap water. Cardador and Gallego (2015) measured levels of 10 HAAs in 2 100% juice products (0.07 μg/L to 0.08 μg/L), 37 reconstituted juices (mean = 4.5; 0.5 μg/L to 31 μg/L), 32 nectar juices (mean = 6.7; 0.2 μg/L to 22 μg/L), and 55 soft drinks (mean = 12; 0.3 μg/L to 73 μg/L) sold in Spain. The mean for soft drinks was increased by inclusion of tonic water (mean = 40.2 μg/L) and soda water (mean = 33.5 μg/L) which had higher levels than other drinks sampled.

### 2.7.4 Potential Exposure from Foods

HAAs may be present in natural foods in relatively low amounts, but preparation of food by rinsing before or after cooking or cooking in treated water may add to the levels. Another potential source of HAAs is reaction of iodide in iodized table salt with chlorine in tap water to form hypoiodous acid (HOI), which can react with residual organic matter in tap water and organic matter from food to form iodinated disinfection by-products (Becalski et al. 2006; Pan et al. 2016).

Solid and liquid phases of canned vegetables can contain disinfection by-products from contact with treated water and chemicals used in the canning process (e.g., washing, sanitizing, blanching, and filling with sauces or brine solutions) (Cardador and Gallego 2017). HAAs have been found to be predominant in the liquid phase, which is consistent with their ionic and nonvolatile characteristics.

A limited range of six foods—chicken, three vegetables, dried beans, and pasta—were cooked in purified water, which would not be expected to contain disinfection by-products, and analyzed for nine HAAs; all six foods contained dichloroacetic acid (31 ng/g to 100 ng/g) and trichloroacetic acid (19 ng/g to 81 ng/g) with one to five other HAAs also detected (Raymer and Michael 2010). During controlled laboratory experiments reported by Raymer and Michael, several foods (frozen carrots and green beans, dried pinto beans, chicken, spaghetti, and lettuce) were cooked in haloacetic acid-spiked water, and uptake of the total HAAs available in the cooking water into the food was reported to be as high as 85% (for uptake of dibromoacetic acid by dried pinto beans) although uptake was generally in the range of 2% to 25% for other foods and HAAs. Raymer and Michael also estimated intakes of HAAs from food based on the uptake of HAAs from water containing the MCL of 60 μg/L and reported 3.75 μg per serving for cooked green beans and 6 μg per serving for cooked pasta.

Foods, both canned and fresh, are generally washed with or soaked in treated water and are cooked in treated water. The median amounts of HAAs expressed in μg per kg of food range from less than 1 μg/kg for milk to greater than 10 μg/kg for soft drinks, prepared salads, and minimally processed vegetables such as fruits or vegetables washed with chlorine-based chemicals in water (Cardador and Gallego 2017). Canned vegetables, fruit juices, and cheese fall between these levels. Canned vegetables generally contain several-fold higher levels of HAAs in the liquid phase than the solid phase because of their ionic and polar nature.

### 2.7.5 Potential Exposure from Other Sources

#### Occupational Exposure to Swimming Pool Attendants

No data were found for other potential occupational exposures to HAAs, but limited information was found for exposure to swimming pool attendants. HAAs are neither volatile nor appreciably skin permeable (Regli et al. 2015; Xu et al. 2002), but studies of haloacetic acid exposure from indoor and outdoor swimming pools indicate that limited inhalation and dermal exposure also can occur (e.g., ingestion ~94% contribution, inhalation ~5%, and dermal ~1%) (Cardador and Gallego 2011). The authors also reported that HAAs (mostly dichloroacetic acid) can get into the atmosphere of indoor swimming pools through aerosols in ambient air and be inhaled.

The HAAs mono-, di-, and trichloroacetic acid have been measured in the urine of swimmers, and di- and trichloroacetic acid have been measured in the urine of swimming pool attendants (Cardador and Gallego 2011; IARC 2014; Kim and Weisel 1998). After 2 hours of exposure, indoor pool attendant urine samples contained 313 ng/L [0.313 µg/L] dichloroacetic acid and 120 ng/L [0.120 µg/L] trichloroacetic acid (Cardador and Gallego 2011). After 4 hours, indoor attendant urine samples contained 450 ng/L [0.45 µg/L] dichloroacetic acid and 139 ng/L [0.139 µg/L] trichloroacetic acid. Outdoor pool attendant urine samples contained 51 ng/L [0.051 µg/L] dichloroacetic acid after 2 hours of exposure and 58 ng/L [0.058 µg/L] dichloroacetic acid after 4 hours of exposure. No trichloroacetic acid was detected in the urine of outdoor pool attendants.

#### Releases to the Environment

Although some haloacetic acids, such as trichloroacetic acid, dichloroacetic acid, and chloroacetic acid have some uses in industry or medicine, only chloroacetic acid (of the 13 haloacetic acids being reviewed) is on the Toxics Release Inventory (TRI) reporting list for 2015 (the most recent year for which TRI data are available). Total reported on- and off-site release of chloroacetic acid was approximately 5,470 pounds from 19 U.S. facilities in 2015 (TRI 2017). Calculations based on media-specific release data from TRI indicate that releases to air accounted for 94.8% of total releases, off-site disposal for 4.6%, and land for 0.6%.

#### Overall Potential for Exposure to HAAs

Individuals living in the United States are exposed to HAAs primarily from drinking treated tap water or other beverages prepared from treated water with additional exposure likely from foods that are prepared using treated water. Consumption of water from all foods and liquids per day has been estimated by CDC (Rosinger and Herrick 2016) to be 3.46 L for men over 20 and 2.75 L for women over 20. The contribution from plain water, i.e., tap water, is approximately 1/3 (33.3%) of the total. The Institute of Medicine estimates that 20% of total water consumption is derived from foods, and the remaining 46.7% would derive from beverages such as tea, coffee, soft drinks, and fruit drinks.

No data were identified that provided overall estimates for consumption of HAAs; however, based on the MCL for HAA5, and assuming that all water consumed contained HAAs at that level, total water consumption would result in exposure to approximately 210 μg per day for men and 165 μg per day for women in the United States. Data for U.S. water facilities serving communities of all sizes in 2011 indicate a median value for HAA5 of 20.1 μg/L with the 5^th^ percentile at 2.0 μg/L and the 95th percentile at 59.0 μg/L. The median exposure would therefore be about 69 μg per day (5% to 95% = 6.9 μg to 204 μg per day) for men and 55 μg per day (5% to 95% = 5.5 μg to 162.2 μg per day) for women. At the median exposure and above, these levels will likely overestimate actual exposure for most people since the data reported above for beverages such as fruit drinks and soft drinks and for foods prepared with treated water suggest lower concentrations of HAAs compared with the typical water supply. In addition, any effort to determine total consumption of HAAs would need to take into account consumption of bottled water and point-of-use filtration methods in the home (Wright et al. 2006).

Relatively few data on potential exposure to HAAs from other sources such as swimming pools and spas; cooking and food; and point-of-use disinfection have been found, but the following information has been identified:

- HAAs form in swimming pools or spas disinfected with chlorine-based disinfectants and detectable levels of both dichloroacetic acid and trichloroacetic acid have been reported in swimming pool water and in urine samples from swimming pool attendants.
- Data were identified for HAAs in only a few foods, but each of the HAA9 components was detected in one or more common foods cooked in purified water that would not be expected to contain HAAs.
- Use of HAA-spiked water to cook food or to rinse food after cooking resulted in measurable uptake of HAAs. Estimates of possible intakes from such uptakes indicate several μg per serving could be consumed due to cooking food with treated water.
- Point-of-use disinfection methods based on iodine-containing disinfectants have been shown to result in formation of HAAs, but the use of these methods is limited.

## 2.8 Summary and Synthesis

Disinfection of water has achieved tremendous public health benefits in the United States and worldwide through reduction in exposure of individuals to disease-causing microorganisms. However, a side effect of water treatment is that over 250,000,000 people in the United States are exposed to chlorinated drinking water, indicating that a significant number of people in the United States are exposed to mono-, di-, and trihaloacetic acids found as water disinfection by-products. Ingestion of chlorinated drinking water is the most common exposure route for HAAs, but inhalation and dermal exposure also can occur. Other potential sources of exposure to HAAs include swimming pools and spas, cooking and food, and point-of-use disinfection. Disinfection by-products are formed from the reaction of chemical disinfectants (e.g., chlorine, chloramines, chlorine dioxide, or ozone) with organic precursors, and inorganic precursors (most often certain halide ions, i.e., bromide [Br^–^] or iodide [I^–^]). The primary factors affecting the formation of disinfection by-products are (1) source water quality and characteristics, (2) types and concentrations of precursors, and (3) type of disinfection method and dose.

Anthropogenic and natural sources of bromide and iodide can increase concentrations of these halide ions in source waters (e.g., due to incomplete removal or non-removal in wastewater treatment plants) and create brominated and iodinated HAAs and other disinfection by-products such as trihalomethanes and bromate.

Remediation of haloacetic acid disinfection by-products can be divided into three general approaches: (1) removal of precursors prior to disinfection, (2) optimization or modification of disinfection practices (e.g., altering disinfectant type, dose, or application point in the water treatment process), and (3) removal of disinfection by-products after formation.