# 1 Properties

Water disinfection is among the most important and beneficial public health advances of the 20th century in the United States and worldwide (Calderon 2000). Disinfection of water has substantially reduced the incidence of cholera, typhoid, and amoebic dysentery caused by waterborne pathogens and has contributed to decreases in infectious diseases and increases in life expectancy (Richardson et al. 2007). The use of chlorine-based disinfection methods for public water supplies began in the early 1900s in the United States (USEPA 2000). Beginning in the 1970s, the formation of disinfection by-products (DBPs) in water due to the reaction between organic precursors in the source water and disinfection agents, primarily chlorine-based, was recognized as a concern (CDC 2016). Since that first discovery, more than 500 unique DBP molecules have been identified, including many different halogen-containing molecules such as haloacids. The two major classes of DBPs by weight are trihalomethanes and haloacetic acids.

## 1.1 Haloacetic Acids Identified in Disinfected Water

Haloacetic acids all share a common structure with acetic acid as the parent compound, thus these molecules consist of two carbons, including a carboxylic acid and an alpha carbon. A total of 34 different mono- (4 molecules), di- (10 molecules), and trihaloacetic acids (20 molecules) can be formed by replacement of one or more of the 3 hydrogens on the alpha carbon with members of the halogens class, which include fluorine, chlorine, bromine, and iodine. No fluorine-containing haloacetic acids have been identified as water disinfection by-products, likely because the energy required to form these molecules is higher than the oxidation potential of the disinfectants in current use (chlorine, chloramine, ozone, and chlorine dioxide) (Richardson 2016, personal communication to NTP on September 7, 2016). Thirteen haloacetic acids containing chlorine, bromine, or iodine or a combination of these halogens have been identified in disinfected water and these are discussed in this document (Table 1-1).

Table 1-1 Structures of 13 Haloacetic Acids Present in Disinfected Water

Halogen | Mono-HAA | Di-HAA | Tri-HAA
Chlorine | Monochloroacetic acid (MCA) | Dichloroacetic acid (DCA) | Trichloroacetic acid (TCA)
Bromine | Monobromoacetic acid (MBA) | Dibromoacetic acid (DBA) | Tribromoacetic acid (TBA)
Iodine | Monoiodoacetic acid (MIA) | Diiodoacetic acid (DIA) | –
Chlorine and bromine | – | Bromochloroacetic acid (BCA) | Bromodichloroacetic acid (BDCA); Chlorodibromoacetic acid (CDBA)
Iodine and chlorine or bromine | – | Bromoiodoacetic acid (BIA); Chloroiodoacetic acid (CIA) | –

In 1998, EPA first regulated the sum of five haloacetic acids (HAA5) in drinking water (chloroacetic acid, bromoacetic acid, dichloroacetic acid, dibromoacetic acid, and trichloroacetic acid) (Federal Register 1998). In 2016, EPA required monitoring for four additional haloacetic acids (bromochloroacetic acid, bromodichloroacetic acid, chlorodibromoacetic acid, and tribromoacetic acid) in the Fourth Unregulated Contaminant Monitoring Rule (UCMR4) (Federal Register 2016) to encompass a group of haloacetic acids collectively referred to as HAA9.

Four HAAs containing one or more iodine atoms have been detected in treated water, but they are not currently regulated in the United States. Iodoacetic acid and bromoiodoacetic acid were identified in drinking water for the first time by Weinberg et al. (2002). In other laboratory studies of water treatment and uses of treated water, Smith et al. (2010b) showed that diiodoacetic acid was formed in water treated by point-of-use disinfection with iodine tincture, and Becalski et al. (2006) showed that chloroiodoacetic acid was formed from boiling chlorinated tap water with iodized table salt. The 13 HAAs identified in treated water (see Table 1-1) will be discussed in this monograph.

## 1.2 Physical and Chemical Properties

The halogens—fluorine, chlorine, bromine, and iodine—are reactive elements that form a family or group of elements in the periodic table; however, fluorine-containing haloacetic acids are not considered further in this monograph as noted in Section 1.1. The presence of halogen atoms affects the reactivity of a haloacetic acid, particularly the reactivity of the alpha carbon to which the halogens are attached and the ionizability of the carboxylic acid. Physical-chemical properties of the halogens that affect the reactivity of the haloacetic acids include electronegativity, polarizability, the physical size of these atoms, and related properties such as the strength of the bond between the halogen and a carbon atom and the potential of a halogen to act as a leaving group.

Electronegativity is defined as the tendency of an atom or functional group to attract electrons from other atoms in a molecule. The electronegativity of the halogens decreases with increasing atomic number moving down the periodic table from chlorine to bromine to iodine. The presence of one or more halogen atoms in a haloacetic acid will affect (1) the strength of the negative charge resulting from ionization of the carboxylic acid, (2) the magnitude of the negative log of the acid dissociation constant (pK_a_) of the carboxylic acid, and (3) the reactivity of the alpha carbon in a substitution reaction. Thus, the physical-chemical characteristics of each haloacetic acid depends on the type and number of halogen atoms in the molecule.

The toxic potency of the monohaloacetic acids correlates highly with their electrophilic reactivity or alkylating potential and the quality of the halogen as a leaving group (Pals et al. 2011; Plewa et al. 2004a). The atomic size of the three halogens from smallest to largest is Cl < Br < I, and the length of the carbon-hydrogen bond increases in the same order while the bond dissociation energy decreases (Plewa et al. 2004a). The quality of each halogen as a leaving group also increases from chlorine to bromine to iodine and is related to the polarizability of the halogen atom (i.e., the ability of the electrons in the atom to distort or shift due to external influences) and delocalization of the electron cloud (i.e., the spatial distribution of electrons shared among the atoms in a molecule). Both polarizability and delocalization are highest for iodine among the halogens.

An important substitution reaction mechanism in organic chemistry consists of the breaking of one bond and the simultaneous formation of another between reacting molecules. This mechanism is described as “substitution, nucleophilic, with 2 molecules in the rate-determining step” and is commonly abbreviated as S_N_2. The S_N_2 reactivity of the monohaloacetic acids increases from chloride to bromide to iodide (Plewa et al. 2004a).

Three physical-chemical properties likely to be related to the toxicity of the HAAs because they describe the ability of the molecules to enter cells and their potential reactivity with other molecules within a cell are the octanol-water partition coefficient (log K_ow_), the pK_a_, and the energy of the lowest unoccupied molecular orbital for the deprotonated form of the HAAs that exists in solution at physiological pH (E_LUMO_) (Table 1-2). At physiological pH, all of the haloacetic acids will exist in their ionized form, but the pK_a_ also indicates the strength of the acid form which increases as pK_a_ decreases. The relationship between these physical-chemical properties and the toxicity and potential mechanisms of carcinogenicity of haloacetic acids as a class is discussed further in Section 7.2. QSAR models using these physical-chemical properties have shown significant correlations with endpoints such as the cytotoxicity and genotoxicity of HAAs when two parameters, usually E_LUMO_ and pK_a_, are used in combination but not when either parameter was used by itself (Pals et al. 2011; Plewa et al. 2010; Plewa et al. 2004b; Richard and Hunter 1996; Schultz et al. 2006; Stalter et al. 2016a).

Table 1-2 Properties of Haloacetic Acids

Haloacetic Acid | CAS No. | Formula | Molecular Weight | Solubility in Water (g/100 mL)^a^ | Vapor Pressure (mm Hg)^a,b^ | Dipole moment (Debye Units)^c^ | Octanol-water Partition Coefficient (log K_ow_)^d^ | Dissociation Constant (pK_a_)^d^ | Energy of Lowest Unoccupied Molecular Orbital, E_LUMO_ (eV)^d^
Chloroacetic acid | 79-11-8 | C_2_H_3_ClO_2_ | 94.5 | 85.8 | 0.065 | 2.716 | 0.22 | 2.97 | 9.43
Bromoacetic acid | 79-08-3 | C_2_H_3_BrO_2_ | 138.9 | 9.4 | 0.119 | 2.722 | 0.41 | 2.96 | 8.68
Iodoacetic acid | 64-69-7 | C_2_H_3_IO_2_ | 185.9 | − | 0.03 | 1.794 | 0.85 | 2.95 | 7.18
Dichloroacetic acid | 79-43-6 | C_2_H_2_Cl_2_O_2_ | 128.9 | 100 (at 20°C) | 0.179 | 1.284 | 0.92 | 1.41 | 8.44
Dibromoacetic acid | 631-64-1 | C_2_H_2_Br_2_O_2_ | 217.8 | 211 | 0.023 | 1.048 | 0.7 | 1.39 | 7.51
Diiodoacetic acid | 598-89-0 | C_2_H_2_I_2_O_2_ | 311.8 | − | − | 2.163 | 1.3^e^ | − | −
Bromochloroacetic acid | 5589-96-8 | C_2_H_2_BrClO_2_ | 173.4 | 25 | 0.14 | − | 0.61 | 1.4 | 7.78
Chloroiodoacetic acid | 53715-09-6 | C_2_H_2_ClIO_2_ | 220.4 | − | − | − | 1.2 | 1.47 | 6.40
Bromoiodoacetic acid | 71815-43-5 | C_2_H_2_BrIO_2_ | 264.8 | − | − | − | 1.4 | 1.67 | 6.46
Trichloroacetic acid | 76-03-9 | C_2_HCl_3_O_2_ | 163.4 | 4.4 | 0.06 | 1.564 | 1.33 | 0.66 | 7.13
Tribromoacetic acid | 75-96-7 | C_2_HBr_3_O_2_ | 296.7 | 20 | 0.00028 | 1.552 | 1.71 | 0.03 | 6.12
Bromodichloroacetic acid | 71133-14-7 | C_2_HBrCl_2_O_2_ | 207.8 | 0.49 | 0.036 | − | 1.53 | 0.05 | 6.65
Chlorodibromoacetic acid | 5278-95-5 | C_2_HBr_2_ClO_2_ | 252.3 | 0.24 | 0.0052 | − | 1.62 | 0.04 | 6.42

^a^ Reported at 25°C (298.15°K) unless noted otherwise.

^b^ PubChem (2017), except chloroacetic acid, bromoacetic acid, and dichloroacetic acid from ChemIDplus (2017).

^c^ Pérez-Garrido et al. (2008).

^d^ Stalter et al. (2016a) unless noted otherwise; deprotonated form.

^e^ PubChem (2016a).