# Peer Review

Peer review of the draft RoC Monograph on Haloacetic Acids Found as Drinking Water Disinfection By-products was conducted by an ad hoc expert panel at a public meeting held July 24, 2017, in the Rodbell Auditorium at the National Institute of Environmental Health Sciences, David P. Rall Building, Research Triangle Park, NC (see https://ntp.niehs.nih.gov/go/38854 for meeting materials, public comments, and peer review report (panel recommendations) from meeting). The selection of panel members and conduct of the peer review were performed in accordance with the Federal Advisory Committee Act and federal policies and regulations. The panel members served as independent scientists, not as representatives of any institution, company, or governmental agency.

The charge to the Peer-review Panel was as follows:

1. Comment on whether the draft RoC Monograph on Haloacetic Acids Found as Water Disinfection By-products is technically correct, clearly stated, and objectively presented.
2. Provide opinion on whether there is currently or was in the past significant human exposure to haloacetic acids found as disinfection by-products.

The panel was asked to vote on the following questions:

1. Whether the scientific evidence supports NTP’s conclusions on the level of evidence for carcinogenicity from cancer studies in animals for six individual haloacetic acids found as water disinfection by-products.
2. Whether the scientific evidence supports NTP’s preliminary policy decision on the listing status of six individual haloacetic acids found as water disinfection by-products.

The monograph was revised based on NTP’s review of the panel’s peer-review comments. The Peer-review Panel Report, which captures the panel recommendations for listing status of haloacetic acids found as water disinfection by-products in the RoC and their scientific comments, are available on the Peer-Review Meeting web page for haloacetic acids (https://ntp.niehs.nih.gov/go/38854).

At a public meeting on December 7, 2017, NTP provided the NTP Board of Scientific Counselors with information about the peer review and finalized the RoC monograph for Haloacetic Acids Found as Water Disinfection By-products after the meeting.

The final monograph does not include the draft profiles for the six haloacetic acids recommended for listing as reasonably anticipated to be a human carcinogen. As per the RoC process (https://ntp.niehs.nih.gov/pubhealth/roc/process/index.html), NTP submits the draft substance profiles for newly reviewed substances with their recommended listing status to the NTP Executive Committee for consultation and then to the Secretary of Health and Human Services for review and approval. Upon their approval by the Secretary, the substance profiles for newly reviewed substances are added to the next edition of the RoC and the RoC is prepared in electronic format, transmitted to Congress, and published on the NTP website.

## Peer Reviewers

- Weihsueh Chiu, Ph.D. (Chair)
  Professor
  Department of Veterinary Integrative Biosciences
  College of Veterinary Medicine and Biomedical Biosciences
  Texas A&M University
  College Station, Texas, USA
- Julia H. Carter, Ph.D.
  President and Chairman
  Wood Hudson Cancer Research Laboratory
  Newport, Kentucky, USA
- Lawrence H. Lash, Ph.D.
  Professor and Associate Chair
  Wayne State University School of Medicine
  Detroit, Michigan, USA
- Shahid Parvez, Ph.D.
  Assistant Professor
  Environmental Health Science
  Richard M. Fairbanks School of Public Health
  Indiana University–Purdue University Indianapolis
  Indianapolis, Indiana, USA
- Mathias Attene-Ramos, Ph.D.
  Associate Professor
  Department of Environmental and Occupational Health
  George Washington University
  Washington, District of Columbia, USA
- Stephen M. Roberts, Ph.D.
  Director and Professor
  Center for Environmental and Human Toxicology
  University of Florida
  Gainesville, Florida, USA
- Consolato Sergi, M.D., Ph.D., FRCPC
  Professor
  Medicine and Dentistry
  Laboratory Medicine and Pathology
  University of Alberta
  Edmonton, Alberta, Canada
- Susan C. Tilton, Ph.D.
  Assistant Professor
  Environmental and Molecular Toxicology
  Oregon State University
  Corvallis, Oregon, USA