# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Responsible for oversight and coordination of activities including conception, design, and planning of the cancer hazard evaluation
  Gloria D. Jahnke, D.V.M., DABT, Project Co-lead
- Contributed to design, conduct, technical review, and writing of cancer hazard evaluation, and the interpretation and integration of studies in the evaluation
  Ruth M. Lunn, Dr.P.H.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Responsible for oversight and coordination of activities including conception, design, and planning of the cancer hazard evaluation
  Stanley T. Atwood, M.S., Project Co-lead
- Contributed to design, conduct, technical review, and writing of the cancer hazard evaluation, and interpretation and integration of studies in the evaluation
  Andrew Ewens, Ph.D.
  Sanford C. Garner, Ph.D.
  Alton Peters, M.S.